# ACKNOWLEDGMENTS

The authors are grateful to the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- M. Jason Highsmith, PhD, DPT, CP, FAAOP
  National Program Director
  Orthotic, Prosthetic & Pedorthic Clinical Services (OPPCS)
  Rehabilitation and Prosthetic Service (10P4R)
- David Chandler, PhD
  Chief
  Rehabilitation and Prosthetic Service (10P4R)
- Lucille Beck, PhD
  Deputy Under Secretary for Health for Policy and Services (10P)
  Veterans Health Administration

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Joseph B. Webster, MD
  National Medical Director
  VA Amputation System of Care
- Jeffrey M. Robbins, DPM
  Director Podiatry Program
  VACO
- Jeffrey Heckman, DO
  Director of the Regional Amputation Center
  VA Puget Sound Health Care System
- Daniel C. Norvell, PhD
  Senior Research Epidemiologist
  Center for Limb Loss and Mobility, VA Puget Sound Health Care System
- Joseph Czerniecki, MD
  Investigator
  Center for Limb Loss and Mobility, VA Puget Sound Health Care System

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix D for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.