# DISCUSSION

## KEY FINDINGS

- The PODUS 2020 risk prediction tool, referred to by the authors as a clinical prediction rule (CPR), has the most favorable prognostic accuracy and feasibility characteristics for use in the clinic setting to predict risk of primary or recurrent DFU at 2 years.
- We did not identify any risk prediction tools for amputation or non-DFU-healing in patients with current DFU over a specified time horizon.
- Although PODUS 2020 predicts risk of DFU at 2 years, no data exist to inform how risks for DFU change over time and the appropriate re-screening intervals for any tool.
- Tools with good prognostic accuracy, especially those developed in non-Veterans, need to be validated in a primary care VA population prior to implementation. Limited evidence suggests that offloading and therapeutic footwear may prevent the development of primary and recurrent DFU though uncertainty remains regarding comparative effectiveness.
- While methodological limitations exist in the primary literature and systematic reviews of accommodative insoles, Total Contact Casts (TCC) and available removable devices may improve DFU healing.
- Intervention adherence was low and research to identify adherence barriers and facilitators is needed.

In this overview of reviews, we found 30 SRs with data relevant to 1 of the 3 established key questions. We found 6 SRs related to KQ1, 17 SRs and 1 overview related to KQ2, and 10 SRs related to KQ3. The majority of the included SRs incorporated mixed study designs and summarized the findings narratively or qualitatively. We summarize the findings of the most recent low and moderate ROB SRs, as they capture much of the evidence presented in older SRs while also including the newly introduced tools and interventions.

DFUs have severe consequences for the individual and health care systems providing foot care.^49^ Prognostic models which predict risk of DFU can aid in targeted monitoring and focused prevention for high-risk patients while reducing unnecessary and time/resource-intensive additional monitoring or referrals for lower-risk individuals. We found 2 recent SRs that identified tools and models predicting risk of DFU or amputation and assessed their performance characteristics.^16,19^ Although both SRs included studies published in PubMed and EMBASE databases over similar time frames, they identified different models and tools and reached different conclusions. The disparate findings in the 2 SRs are likely due to differences in the study populations included, search terms, and eligibility for inclusion of non-validated tools/models. Thus, in contrast to Beulens et al which identified prediction models, Fernandez-Torres et al mostly identified clinician assessment or risk-classification tools without a prediction time horizon. Models or tools that do not provide a time frame for risk prediction cannot provide an absolute risk estimate over a given time period for the patient and are less useful for shared clinical decision-making between providers and patients.

Based on the results of the identified studies, we considered 4 models/tools for clinical use – 4 which predicted risk for DFU (Boyko et al, PODUS 2020, Martins-Mendes original, Martins-Mendes simplified) and 2 which predict amputation (Martin-Mendes et al, original and simplified). All 4 models predict first and recurrent DFU and include prior DFU as a risk factor. Our search did not identify any tools which exclusively predicted first DFU (ie, primary prevention of DFU).

A prerequisite for tool application to clinical practice is adequate prognostic accuracy (judged by discrimination and calibration). In external validation studies, all 4 models/tools predicting DFU at 2 or 5 years and the 2 models predicting amputation at 5 years had good to excellent discrimination (C statistic >0.75).^16,46^ Calibration was only reported for the 2 models by Martin-Mendes et al (original model and simplified model) for outcomes of either DFU or amputation at 5 years and PODUS 2020 for outcome of DFU at 2 years. For these 3 models, calibration was good in the lower predicted risk categories but suboptimal in the higher predicted risk groups.

The model developed by Boyko et al is discussed in more detail because it was initially developed in Veterans in a primary care setting with external validation of the model using a Dutch cohort. Boyko et al recruited Veterans, primarily male (98%), with type 2 diabetes from Seattle VA primary care clinics (n=1285). Participants had long-standing diabetes that was poorly controlled (mean duration >10 years and HbA1c approximately 10%); 30% had a history of DFU or amputation. Over a mean follow-up of 3.4 years, 16.8% of veterans developed a DFU.^42^ In the external validation study,^16^ the model was evaluated in a cohort with type 2 diabetes seen in primary care clinics in the Netherlands (n=7,624) that had a much lower risk of DFU. In this cohort, only 4.1% had a history of DFU or amputation, and during the 5 years of follow-up only 6.4% developed a DFU and 0.9% underwent amputation. The model performed well in validation studies, showing good discrimination for DFU prediction at 1 year and 5 years in the Veteran cohort (C-statistic 0.81 and 0.76, respectively; internal validation) and for DFU prediction at 5 years in the Dutch cohort (C-statistic 0.81; external validation). The internal validation study did not provide information on calibration, and the external validation study provided calibration plots for the model only after recalibration – results which are subject to optimism and likely fail to accurately reflect model performance in other cohorts. Furthermore, this prognostic model does not provide an absolute risk of DFU based on score.

We also reviewed the Prevention of Amputation in Veterans Everywhere (PAVE) tool used clinically in the VA.^50^ This tool, which is a risk-classification system, is recommended to be used annually by primary care clinicians in all Veterans with diabetes to assess DFU risk and provide risk thresholds for podiatric referral to individuals without DFU who are judged to be at moderate or high risk for foot complications (PAVE 2 or 3), including any individual with a current or prior DFU. PAVE consists of 6 binary variables: neuropathy (defined as insensate to monofilament testing); PAD (defined as the absence of any dorsalis pedis or posterior tibial pulse); evidence of severe PAD (eg, intermittent claudication, rest pain, gangrene, or peripheral bypass surgery); prior DFU or amputation, mechanical deformity; or end-stage renal disease. The results are weighted according to risk variable and classify patients as normal (PAVE 0), low (PAVE 1), moderate (PAVE 2), or high risk (PAVE 3) for foot complications. Scoring does not require a calculation tool and is a clinical reminder available through the VA electronic medical record. Identification of increased risk by PAVE (PAVE score of 1 or greater) prompts referral to specialists (podiatrists) for close monitoring, correction of modifiable factors, and preventative interventions. Despite the many favorable clinical applicability characteristics, we did not find any developmental or validation studies for PAVE that evaluated prognostic accuracy or time horizons for prediction.

Finally, the PODUS 2020, which the authors describe as a clinical prediction rule (CPR), was developed in a large population (n=8,255) using data from 4 international cohorts in Europe and the US. It is composed of 3 binary variables (neuropathy, absence of any pedal pulse, or prior history of DFU or amputation). The percent of patients with a prior history of DFU or amputation was 8.5% in the developmental cohort, and 5.2% of all participants developed a DFU at 2 years. Clinical prediction scores of 0, 1, 2, 3, and 4 had a risk of DFU within 2 years of 2.4%, 6.0%, 14.0%, 29.2%, and 51.1%, respectively. PODUS 2020 has also externally validated in an independent cohort (n=3324), in whom the absolute risk of DFU development at 2 years was 3.9%. In this validation cohort, PODUS 2020 had excellent discrimination and good calibration (except in the highest risk quintiles).

PODUS 2020 has not been validated in the Veteran population, with a possibly higher absolute risk of DFU development (based on select data by Boyko et al); as such the performance of PODUS 2020 in Veterans is unknown. Based on their findings, the PODUS 2020 authors also concluded that referral and subsequent monitoring and treatment for individuals with an estimated 2-year probability of DFU of 6% or more (CPR score = 1) would result in 15 additional individuals being correctly identified as an ulcer case at 2 years per 1000 individuals screened without increasing the number considered unnecessarily referred. Use of a threshold of an estimated 2-year probability of DFU of 14% or higher (CPR score = 2) would result in 10 additional cases of DFU being correctly identified at 2 years per 1000 individuals screened without increasing the number considered unnecessarily referred. However, it is not known if implementation of the CPR and subsequent referral, monitoring, or treatment prevents development of DFU or amputations.

Clinical applicability is a critical consideration that drives widespread uptake, use, and implementation of a prediction model/tool. Given the time constraints in primary care clinics with competing priorities for clinicians, the ideal model/tool includes evaluation of only a few readily obtainable variables and ease of prediction. The 4 models/tools under consideration, Boyko et al, Martins-Mendes et al (original and simplified), and PODUS 2020, included 2 to 7 variables. Although the simplified models by Martin-Mendes et al which predict either DFU or amputation have the least number of variables (2), the single variable of diabetes complications entails an assessment for presence of 7 complications. Furthermore, the models by Martin-Mendes et al (original and simplified) also require a calculation tool to ascertain risk. The model by Boyko et al evaluates 7 variables and requires an evaluation of vision and laboratory data in addition to a calculation tool to ascertain risk. These factors decrease the feasibility of widespread implementation of these models in busy primary care clinics. In contrast, PODUS 2020 consists of 3 binary variables that can be measured in the clinic with a simple numerical scoring system that predicts absolute rate of DFU by 2 years.^46^ Calculation of the score is simple and clinically intuitive and provides an average absolute risk estimate for DFU at 2 years for the different scores (0-4). Since PODUS 2020 predicts DFU development at 2 years, it can be calculated biennially as opposed to annually. Hence, based on our review, the PODUS 2020 model, referred to by the authors as a CPR, has the most favorable prognostic accuracy and feasibility characteristics for use in the clinic setting to predict primary or recurrent DFU development. It is also the only prediction tool that provides an absolute rate of DFU development at 2years — information that is highly relevant for shared decision-making between physicians and patients. We also identified some limitations for PODUS 2020.^46^ Despite its simplicity, it will take time to conduct in primary care clinics where patients and clinicians have competing health care priorities and limited time and resources. The prognostic performance of PODUS 2020 depends on the ability of clinicians to accurately use a 10 g monofilament to assess for neuropathy and assess for palpable pedal pulses. Although our evidence review did not formally conduct a primary literature review of the performance characteristics of the clinically assessed variables included in PODUS 2020, one study showed sub-optimal validity and reliability (inter- and intra-rater).^44^ Performance characteristics for these variables (neuropathy and arterial disease) likely also varies based on clinicians’ specialty and experience. Future research could formally examine the literature for studies describing the performance characteristics of these clinically assessed variables or conduct such studies if not done. PAVE consists of 6 variables which may be time consuming to obtain annually in busy primary care clinic settings, especially for variables unlikely to change over time: neuropathy or lack of palpable pulses.

Lastly, all studies of the identified tools, including PODUS 2020, assessed 1-time use of the tool to predict DFU development or amputation at subsequent time horizons ranging from 1 to 5 years (2 years for PODUS 2020). There were no studies of sequential use of the tools at defined time intervals to identify how risks for DFU development change over time. Although VA guidelines recommend re-screening annually for DFU risk using PAVE, the benefit of re-screening or the appropriate re-screening interval (if re-screened) for DFU risk with any tool is unknown.

Patients with current DFU often have poor outcomes including amputation. However, we did not identify any prediction tools for amputation or non-healing in patients with DFU over a specified time horizon.

We identified 24 SRs addressing orthotics for either DFU prevention or treatment. However, despite the number of available reviews, a final conclusion as to whether orthotic interventions are effective or the most effective for prevention or treatment of DFU is uncertain. Interventions for the prevention and treatment of DFU are overshadowed by the noted lack of patient adherence to these interventions.^12,32,35,36^ Lazzarini et al note that even the best offloading device will be ineffective if not used.^35^ Alakahoon et al found lower rates of DFU recurrence among adherent populations and suggest that investigation into methods to improve adherence may be warranted.^28^ The review by Healy at al noted that future research needed to address the issue of adherence to accurately quantify the impact of removable devices.^36^ The review by Jarl et al which captured adherence as a primary outcome found little to no evidence identifying specific factors that would predict adherence in the diabetic patient population. As adherence is central to the success of the offloading intervention, the lack of adherence or capture of adherence rates by primary study authors makes it difficult to assess whether lack of prevention and healing is due to an inferior intervention or lack of use of intervention.

There is inconsistency across the reviews in regard to whether orthotics or removable therapeutic footwear is effective in the prevention and treatment of DFU as well as whether orthotics perform as well as other interventions, such as total contact casts, education, and debridement. van Netten et al rated certainty of evidence down due to inconsistency in the included RCTs’ findings. Crawford et al similarly found evidence to suggest that orthotic interventions may be effective but more research is needed to understand which populations would benefit the most.

Alahakoon et al found that pressure offloading devices were associated with a reduction in the incidence of DFU; however, the included studies were all deemed moderate or high ROB. The evidence supporting orthotic interventions for the prevention and treatment of DFU is limited or inconsistent; similarly, there remains uncertainty as to whether orthotic interventions are more effective than other interventions for DFU prevention and treatment.

The lack of consensus or consistency in effect measure when comparing orthotics of therapeutic footwear across the available reviews may be due in part to study heterogeneity. There was substantial heterogeneity in intervention definition, included populations, and outcomes of interest across reviews. This heterogeneity was driven in large part by the intervention definitions and study populations of the included studies, and several review authors noted the challenges in summarizing the included literature due to this lack of standardization.^11,12,23,25,29,35^ As stated by Bus et al, a persistent obstacle in comparing studies is the lack of standardization not only in definitions but also in the materials and components of an intervention. The recommendation by Bus et al that authors provide a detailed description of interventions included in their studies to aid readers and reviewers in comparing the study findings to available literature remains relevant.^12^

## APPLICABILITY TO VETERANS

Among the identified models/tools for prediction of DFU and amputation, only 1 model was developed in a Veteran population, Boyko et al. Validation of the identified models in primary care Veteran populations is warranted to ascertain the accuracy of the model in this population.

None of the SRs included for KQ2 and 3 provided information separately for Veterans. While results are likely to be applicable to Veterans with diabetes, factors related to patient preference and adherence are important contributors to effectiveness of any therapeutic footwear. Thus, a better understanding of patient preferences and adherence in Veterans based on factors such as age, comorbidities, DFU risk (including prior DFU), foot anatomy, ulcer characteristics and financial co-pays may alter effectiveness and outcomes.

## LIMITATIONS

This evidence review has several limitations. The focus of this review was on prediction tools/models and orthotic interventions for DFU and amputation, and therefore reviews that did not include either of these interventions were excluded. We also limited results to ulcer development, healing, and amputation and excluded reduction in plantar pressures. As the intention of the overview is to provide support for VA policy, outcomes were prioritized to support that endeavor. As the pathway between plantar pressure reduction and ulcer/amputation prevention is tenuous, plantar pressure outcomes were not included. An English language requirement was included and as such may have excluded potentially relevant reviews from the search strategy. However, there were no geographical limitations or date limiters on the search strategy. Many of the included systematic reviews included findings from observational studies which are likely limited by treatment selection and other unmeasured confounders. Many of the systematic reviews and included studies were deemed at least moderate ROB, thus limiting our conclusions. Additionally, most systematic reviews found at best low certainty evidence of effectiveness, especially in those without prior DFU, and almost no information on the comparative effectiveness within categories of pedorthic/orthotic interventions. Thus, it is not possible to provide evidence-based recommendations on specific pedorthic/orthotic options to have available or provide. Such decisions are likely influenced by patient, clinician, and health system preferences as well as costs.

## FUTURE RESEARCH

All current models/tools that predict DFU development include a history of DFU as a risk factor. The large majority of individuals seen in primary care clinics do not have a history of DFU and are likely at much lower risk of developing a DFU or amputation. Thus, future studies should develop and validate models to predict development of first DFU (ie, screening tool for primary prevention) and to determine the feasibility and net benefit of conducting annual (or less frequent) diabetic foot examinations and prognostic tools in all individuals with diabetes. No data exist to inform how risks for DFU change over time and appropriate re-screening intervals for any tool. Thus, it is uncertain how often patients with DM should be screened for risk of DFU or amputation. Frequent screening intervals of 1 year are unlikely to yield better risk stratification. Risk classification systems (eg, PAVE) can be developed further to predict absolute rates at specified time horizons (ie, prediction models). Prior to clinical implementation in the VA, performance characteristics of the individual variables included in the tool and overall model performance in the Veteran population is necessary. In theory, prediction tools will identify high-risk individuals for targeted early interventions, which could decrease DFU and amputation risk. Further research could focus on whether triage decisions based on results of prediction tools are clinically effective leading to improved health outcomes, especially in those without a prior DFU or amputation. Further research is also needed on cost effectiveness and feasibility of referring all patients judged to be at moderate or higher risk of DFU with low absolute risk of DFU to podiatrists. Lastly, further research is also needed on how risks for development of DFU change over time, the incremental benefits and harms of re-screening, and the appropriate screening interval with the tool under consideration for clinical adoption. Thus, more research is needed to evaluate the optimal prediction tool in Veterans, the net benefit of using this model, and the subsequent referral strategies so as to target screening and referral to individuals most likely to benefit.

Future research is needed to assess the effectiveness and comparative effectiveness of orthotic and pedorthic therapeutic footwear options across the wide range of adults with diabetes who have, or are at risk for, DFU. Identifying a “gold standard” for effectiveness (eg, total contact casting) would permit assessment of the comparative effects of different options. Observational studies are unlikely to adequately assess comparative effectiveness given selection and confounding factors between individuals receiving different interventions. Thus, large, long-term RCTs should be prioritized. Providing more complete information on enrolled individuals including age, sex, clinical and foot characteristics would aid in understanding to whom the results pertain. Provision of the intervention, DFU, and outcome characteristics in detail will aid in comparison, allowing for like products and interventions to be grouped appropriately. Future research is needed in understanding patient preferences for therapeutic footwear or other interventions by clinical and foot characteristics as well as patient, caregiver, clinician, and health system barriers and facilitators to adherence.

## CONCLUSIONS

Four well-performing models/tools discriminate the risk of developing primary or recurrent DFU or amputation in adults with diabetes who are ulcer-free at baseline. A history of prior DFU or amputation is a strong predictor for future DFU or amputation in all models. PODUS 2020, which is a prediction tool, has the most favorable prognostic accuracy and is feasible to use in the primary care clinic setting. The PODUS 2020 score predicts DFU development over a 2-year horizon, allowing for an extension of the routine screening interval to 2 years (rather than annually, which is the current VA practice) and perhaps even less frequently if at all in those without a prior DFU history. However, PODUS 2020 has not been externally validated in Veterans. PAVE, the current risk classification tool used in the VA, has no published prognostic accuracy data. For patients with DFUs, we did not identify prediction tools for amputation or healing. The effectiveness of interventions implemented in response to prediction scores to decrease DFU or amputation is unknown.

Therapeutic footwear may prevent recurrent DFU, although evidence is limited and mixed. Offloading footwear may improve DFU healing; however, there is uncertainty regarding which device is most useful and for which populations. Total contact casts generally improved DFU healing compared to controls. Removable cast walkers or removable knee-high walkers may improve DFU healing. Future research should include investigation into enhancing adherence among interventions, detailed accounting of the intervention properties, and stratification by populations to determine the effectiveness of interventions in DFU prevention and treatment.