# RESULTS

## LITERATURE FLOW

The literature flow diagram (Figure 2) summarizes the results of the study selection process (full list of excluded studies available in Appendix B).

Figure 2 Literature Flowchart

## LITERATURE OVERVIEW

Thirty systematic reviews were identified and deemed eligible. One is an overview of systematic reviews,^11^ and the remaining 29 are systematic reviews. Six reviews are relevant to KQ1, 18 to KQ2, and 10 to KQ3. Four reviews were relevant to both KQ 2 and 3.^12–15^ Two reviews for KQ1 were found to be low ROB,^16,17^ 3 moderate ROB,^18–20^ and 1 high ROB.^21^ For KQ2, we found 9 to have low ROB,^11,12,14,22–27^ 3 moderate ROB,^28–30^ and 6 high ROB.^13,15,31–34^ For KQ3, 6 were low ROB,^12,14,35–38^ 1 moderate ROB,^39^ and 3 high ROB^13,15,40^ (Table 2).

A qualitative or narrative approach was identified in 4 reviews for KQ1,^16–18,21^ 16 reviews for KQ2,^11–15,22,24–27,29–34^ and 8 reviews for KQ3.^12–15,36,40^ All of the reviews identified for KQ1 only included observational studies. Three of the 6 reviews were published between 2016 and 2021.^16,18,19^ Among the reviews identified for KQ2, 3 included only RCTs,^23,27,28^ 14 included a mix of RCT and observational studies,^11–15,22,24–26,29–31,33,34^ and 1 included only observational studies.^32^ Eight of the reviews identified for KQ2 were published between 2016 and 2021.^11,22–24,28,29,31,32^ Two of the reviews identified for KQ3 included RCTs only,^38,41^ while the other 8 reviews included both RCT and observational studies.^12–15,35–37,40^ Four of the identified reviews were published between 2016 and 2021^35,37–39^ (Table 2).

Table 2 Summary Characteristics of Eligible Reviews

Characteristic | Reviews (k=30)
| KQ1 (k=6) | KQ2^**^ (k=18) | KQ3 (k=10)
Risk of Bias (ROBIS)
Low | 2 | 9 | 6
Moderate^*^ | 3 | 3 | 1
High | 1 | 6 | 3
Summary Method
Qualitative | 4 | 16 | 8
Quantitative | 1 | 1 | 2
Qualitative and quantitative | 1 | 1 | 0
Year of Review
1999 – 2005 | 0 | 3 | 0
2006 – 2010 | 1 | 1 | 2
2011 – 2015 | 2 | 6 | 4
2016 – 2021 | 3 | 8 | 4
Included Study Design
RCTs only | 0 | 3 | 2
RCT and observational studies | 0 | 14 | 8
Observational studies | 6 | 1 | 0
Review Type
Systematic review | 6 | 17 | 10
Overview of reviews | 0 | 1 | 0

* ROBIS uses the term unclear for reviews that are not identified as low risk of bias but did not rise to the threshold of high risk of bias.

** 4 reviews included capture data for both KQ2 and KQ3.

## KEY QUESTION 1

What are the tool performance characteristics (eg, accuracy, external validation, and implementation) of assessment tools that:

a) Predict development of new diabetic foot ulcers (first or recurrent)?
b) Prognosticate outcomes of diabetic foot ulcers?

### Overview

We identified 3 SRs relevant to KQ1a and 4 SRs relevant to KQ1b that met our eligibility criteria. Detailed characteristics and conclusions of the SRs can be found in Table 3 and Table 4. We describe below the 2 SRs that provide specific recommendations for prognostic models for KQ1a (Beulens et al and Fernandez-Torres et al) and for KQ 1b (Fernandez-Torres et al).^16,19^ Based on the conclusions from these SRs, we identified models that were deemed to be prognostically accurate and clinically useful. We subsequently reviewed primary model development and validation studies (if available) to evaluate prognostic accuracy (calibration and discrimination) and usability. We identified 7 studies that described the initial development and/or validation of the selected models.^42–48^ We identified no studies that evaluated the PAVE tool and looked for external sources for information, including a VA directive, VA local health system educational slides, and a VA webinar.

### Beulens et al 2021

This SR, relevant to KQ1a, identified models/tools to predict development of DFU or amputation in patients with type 2 diabetes (with or without a history of DFU) over a minimal 1-year follow-up period. Studies of models that predict critical limb ischemia or studies that included diabetic patients with current DFUs were excluded. The authors then subsequently performed an external validation of selected models in an independent cohort of Dutch patients with type 2 diabetes using a 5-year follow-up period. We assessed this SR as low ROB.^16^

The Beulens et al SR identified 21 studies of 34 prognostic models/tools that predicted neuropathy, DFU, or amputation with at least 1-year follow up. Of these 34 models, 16 models predicted amputation, 7 predicted DFU, and 6 predicted diabetic polyneuropathy. The commonly used prediction horizons were 1 year and 10 years. The authors reported that most studies were considered to have low to moderate ROB; the few studies with high ROB had limitations in the domains of missing data, model development, and model performance.^16^

The SR authors also conducted an external validation of 13 of the 34 models using a cohort comprised of 7,624 community-dwelling adults with type 2 diabetes seen in a primary care clinic in the Netherlands. The mean age was 67 years, 53% were male, and 4.1% had a history of DFU or amputation. In this cohort, 485 (6.4%) developed a DFU and 70 (0.9%) underwent amputation during the 5 years of follow-up. Among individuals with no history of DFU or amputation (n=7309; 95.9%), 265 (3.6%) developed DFU and 28 (0.4%) underwent amputation over 5 years. In contrast, among individuals with a prior DFU or amputation (n=315), 220 (69.8%) developed a DFU and 42 (13.3%) underwent an amputation at 5 years.

Based on the external validation results, the models that performed well at predicting development of DFU at 5 years were Boyko et al,^42^ PODUS 2015,^45^ and Martins-Mendes et al (original and simplified).^43^ These models had good to excellent discrimination (C statistic 0.76-0.81). No calibration plots were presented for the Boyko et al or PODUS 2015 models for DFU development. Calibration plots shown for the Martins-Mendes models (original and simplified) for development of DFU at 5 years demonstrated good agreement between observed and predicted absolute rates in the lower quintiles of predicted risk, but observed rates exceeded predicted absolute rates (ie, predicted rates from models underestimated actual observed rates) in the higher quintiles of predicted risk.

Based on external validation results, the models that performed well at predicting amputation at 5 years were the Martins-Mendes models (original and simplified) with C-statistics of 0.81 and 0.78, respectively. Calibration plots for these models for amputation prediction showed results similar to their performance for DFU prediction (ie, good agreement for amputation prediction between observed and predicted absolute rates in the lower quintiles of predicted risk), but observed rates exceeded predicted absolute rates in the higher quintiles of predicted risk. The authors concluded that using a combined endpoint of DFU or amputation, the Boyko et al, PODUS 2015, and Martins-Mendes et al models showed good performance with C-statistics of 0.75 or over and may be applicable for use in clinical practice.^16^

The SR authors highlighted the following limitations: (i) low [5-year] incidence of amputation in the external validation cohort (n=70; 0.9%); (ii) the inability to differentiate between major and minor imputations (missing data); (iii) limited generalizability to populations and settings different from their external validation cohort, which consisted of community-dwelling Dutch individuals receiving care in a centrally organized care center; and (iv) inability to validate certain models because the needed variables were not available in the external validation cohort.^16^

### Fernandez-Torres et al 2020

This SR, relevant to KQ1a and 1b, identified clinician-assessment tools for measuring diabetic foot disease and DFU-related variables, which included neuropathy and ulceration risk, and DFU-related variables, which included amputation risk, healing, infection assessment, and measurement applicable to patients with any type of diabetes. Studies of tools that did not include psychometric properties in their development or did not provide any measurement properties that met the consensus-based standards for the selection of health measurement instruments (COSMIN) criteria were excluded. This SR was assessed as moderate ROB.^19^

In this SR, the authors identified 29 studies of 39 clinician-assessment tools validated for the assessment of diabetic foot disease and DFU-related variables. They identified 10 scales assessing neuropathy, 10 assessing ulceration risk, and 17 assessing DFU-related variables. The prediction horizons for these scales were unclear. Thus, measures of calibration and discrimination or absolute risks of DFU-related outcomes over a specific time are not available. Study populations were not described. ROB reporting for the included studies was not available.^19^

Of the 10 tools assessing ulcer risk, the authors identified the Queensland High Risk Foot Form scale (QHRFF) as a valid and reliable instrument for assessing risk of developing a DFU. However, the authors also stated that the psychometric characteristics of QHRFF did not have sufficient strength because the QHRFF validation study was only carried out in 22 subjects. Of the 17 tools for assessment of DFU-related variables, the authors identified the Perfusion, Extent, Depth, Infection, and Sensation (PEDIS) and Site, Ischemia, Neuropathy, Bacterial Infection, and Depth (SINBAD) scales to be valid and reliable. The SR authors concluded that in at-risk populations the QHRFF may be used to [underlined: assess risk of development of DFU]. Also, for amputation risk, healing, infection assessment, and measurement [underlined: in individuals with DFU], the PEDIS and the SINBAD scales may be suitable for clinical use.^19^

Limitations described by the SR authors included possible exclusion of tools that were published in a language other than English, French, Spanish, Portuguese, and Italian, or reported psychometric characteristics not included in the SR’s inclusion criteria.^19^

### KQ 1a Recommended models to predict DFU or amputation in patients with diabetes without a current DFU (with or without a history of prior DFU)

Based on the results and conclusions of the 2 aforementioned SRs, we identified 5 recommended models to predict either DFU or amputation risk in patients without a DFU: Boyko et al, Martin-Mendes et al (simplified and original model), PODUS 2015, and QHRFF. Additionally, based on our literature search, we identified an updated model for PODUS 2015 referred to as PODUS 2020.^46^ Hence, in total we prioritized 6 models for further review and assessment of prognostic accuracy and usability (Appendix E: Supplemental Table 1 and Supplemental Table 2).

We reviewed the original studies describing development and validation of these 6 models.^42–48^ We determined that PODUS 2015 and QHRFF are best categorized as risk classification systems without an absolute prediction rate over a specified time horizon. Since prediction of an outcome over a specific time horizon is important for shared decision-making including specialty referral and intervention, we excluded these risk classification systems from further consideration. We describe below characteristics of the 4 models/tools that predict DFU development or need for amputation over time horizons ranging from 1 to 5 years – Boyko et al, original model by Martin-Mendes et al, simplified model by Martin-Mendes et al, and PODUS 2020. The models by Boyko et al. and Martins-Mendes were prognostic models classifying level of risk over a specific time horizon without an ability to calculate absolute rates, while the PODUS 2020 was a risk prediction tool predicting absolute rate of DFU development over 2 years.

#### Prognostic Accuracy

Prognostic accuracy of the 4 recommended models was measured by discrimination and calibration. Table 5 describes the performance characteristics of the 4 recommended prediction models in their development and validation (internal and external) studies for predicting DFU or amputation over time horizons of 1 to 5 years.

##### Discrimination

[underlined: Predicting DFU development:] In the internal validation cohort studies for predicting DFU development between 1 to 5 years, the models by Boyko et al and Martins-Mendes et al (original and simplified) had good to excellent discrimination (C statistic 0.76-0.81). In external validation studies for DFU prediction, all 4 models, Boyko et al (5-year prediction horizon), Martin-Mendes et al (original and simplified; 5-year prediction horizon), and PODUS 2020 (2-year prediction horizon), had good to excellent discrimination (C statistic 0.76-0.83), with PODUS 2020 performing best.^16,46^

[underlined: Predicting amputation:] In the internal validation studies for predicting amputation at 3 years, the 2 models by Martins-Mendes (original and simplified models) had excellent discrimination (C-statistic 0.83 and 0.81). In the external validation cohort, for prediction of amputation at 5 years, the 2 models by Martins-Mendes (original and simplified) also showed good to excellent discrimination (C statistic 0.78 and 0.81).^16^

##### Calibration

Calibration was assessed by a review of calibration plots and calibration slope.

[underlined: Predicting DFU development:] No models reported calibration in their internal validation cohort studies. Calibration, as reported by external validation studies, was not available for Boyko et al, but was available for the models of Martins-Mendes and PODUS 2020.^16,46^ For the Martins-Mendes models (original and simplified; predicting DFU at 5 years) and PODUS 2020 (predicting DFU at 2 years), calibration plots showed good agreement between observed and predicted absolute risks in the lower quintiles of predicted risk, but observed risks exceeded predicted absolute risks (ie, predicted risks from models underestimated actual observed risks) in the higher quintiles of predicted risk.

[underlined: Predicting amputation:] For the Martin-Mendes models that predicted amputation, no calibration was reported in the internal validation study. The external validation study showed that for amputation prediction at 5 years, similar to results for DFU prediction, both models had good agreement between observed and predicted absolute risks in the lower quintiles of predicted risk, but observed risks exceeded predicted absolute risks in the higher quintiles of predicted risk.

#### Validation

All 4 recommended models have been externally validated. The models by Boyko et al and Martin-Mendes et al (original and simplified) were externally validated in an independent cohort of Dutch community-dwelling individuals with type 2 diabetes with a 5-year follow-up.^16^ PODUS 2020 was validated by the development authors in an independent British cohort with a 2-year follow-up.^46^

#### Usability and Feasibility of Implementation

Table 6 and Supplemental Table 1 describe variables included in the 4 models and score interpretation. The models include variables obtained by history or chart review (prior DFU, prior amputation, and diabetes complications), physical exam (neuropathy, peripheral arterial disease [PAD], fungal infection, and physical impairment), and diagnostic testing in the clinic (visual acuity) or laboratory (microbiology to assess for onychomycosis or tinea pedis, and HbA1c). The number of variables included in the recommended models range from 2 to 7. Most included variables can be ascertained by primary care physicians in the clinic by interview, examination, and review of the medical record. However, models by Boyko et al and Martins-Mendes (original or simplified) are more time intensive and require a calculation tool. PODUS 2020 is a simple risk prediction score ranging from 0-4 and can be assessed in the primary care setting, though calculation of the score requires monofilament testing and palpation of pulses in 4 locations.

### KQ1b Models to predict amputation in patients with a current DFU

Based on the results of the SR by Fernandez-Torres et al, there were 2 recommended models to predict amputation in patients with DFU: PEDIS tool and SINBAD tool (Supplemental Table 3). We reviewed the original studies describing development of these 2 models.^47,48^ Based on this review, we determined that PEDIS and SINBAD were developed as risk classification systems for patients with DFU with no time horizon for risk prediction; hence we excluded these models. Thus, we did not identify any risk prediction tools for predicting risk of amputation in patients with DFU over a specified time horizon.

Table 3 Overview of Systematic Reviews Evaluating Prognostic Models or Risk Prediction Tools for Diabetic Foot Ulcer Development or Amputation in Patients with Diabetes

Author (year); Risk of Bias (ROBIS); Search Dates; Sources; Study Type | Population | Outcome | #Studies/#Models | Authors’ Conclusions | Our Conclusions
Beulens et al (2021)^16^; Low ROB; Inception-10/21/2020; PubMed and EMBASE; Systematic review and external validation study | Patients with type 2 diabetes | Foot ulcer development, amputation, or neuropathy, or a combination of these over a minimal 1-year follow-up | 21/34 | The models by Boyko et al,^42^ PODUS 2015,^35^ and Martins-Mendes et al^43^ performed well to predict outcomes of either amputation or foot ulcer. | PODUS 2015 was developed as a risk classification tool with no time horizon for risk prediction. Hence, it is not a risk prediction model and was excluded from further consideration. The models by Boyko et al and Martins-Mendes et al are prognostic models.
Fernandez-Torres et al (2020)^19^; Moderate ROB; Inception-12/30/2019; PubMed, Scopus, SciELO, CINAHL, Cochrane, PEDro, and EMBASE; Systematic review | Patients with diabetic foot disease including neuropathy, regardless of the type of diabetes | Neuropathy risk, ulceration risk, and diabetic foot ulcer outcome (amputation risk, healing, infection assessment, and measurement) | 29/39 | The Queensland High Risk Foot Form (QHRFF) was valid and reliable for the assessment of ulceration risk. | QHRFF was developed as a risk classification tool with no time horizon for risk prediction. Hence, it is not a risk prediction model and was excluded from further consideration.
Monteiro-Soares et al (2011)^17^; Low ROB; Inception-4/15/2010; MEDLINE; Systematic review | Patients with diabetes, type unspecified | Foot ulcer development | 13/5 | The best method for assessment of risk stratification is not immediately apparent. | Identical to the authors’ conclusions

Table 4 Overview of Systematic Reviews Evaluating Prognostic Models or Prediction Tools for Amputation in Patients with Diabetic Foot Ulcer (DFU)

Author (year); Risk of Bias (ROBIS); Search Dates; Sources; Study Type | Population | Outcome | #Studies/#Models | Authors’ Conclusions | Our Conclusions
Fernandez-Torres et al (2020)^19^; Moderate ROB; Inception-12/30/2019; PubMed, Scopus, SciELO, CINAHL, Cochrane, PEDro, and EMBASE; Systematic review | Patients with diabetic foot disease including neuropathy, regardless of the type of diabetes | Neuropathy risk, ulceration risk, and DFU outcome (amputation, DFU healing, DFU infection assessment, and DFU measurement) | 29/39 | The perfusion, extent, depth, infection and sensation scale (PEDIS) and site, ischemia, neuropathy, bacterial infection, and depth score (SINBAD) tools were valid and reliable for the assessment of amputation risk. | PEDIS and SINBAD were developed as risk classification tools with no time horizon for risk prediction. Hence, they are not prognostic models and were excluded from further consideration.
Monteiro-Soares et al (2020)^18^; Moderate ROB; Unclear; PubMed; Systematic review | Patients with a diabetic foot ulcer | Ulcer-free survival, healing, hospitalization, limb amputation, mortality, and cost | Unclear/19 | No classification could be used to define prognosis in any individual ulcer. | Identical to the authors’ conclusions
Monteiro-Soares et al (2014)^20^; Moderate ROB; Inception-5/31/2013; EBSCO, ISI, PubMed, and SCOPUS; Systematic review | Patients with a diabetic foot ulcer | Amputation | 25/15 | No classification system is ready for wide application. | Identical to the authors’ conclusions
Karthikesalingam et al (2010)^21^; High ROB; 1966-2009; EMBASE and MEDLINE; Systematic review | Patients with a diabetic foot ulcer | “Prognostic accuracy” | 18/11 | No specific recommendation for a scoring system. | Identical to the authors’ conclusions

Table 5 Performance Characteristics of Recommended Prognostic Models or Prediction Tools for Diabetic Foot Ulcer Development or Amputation in Patients with Diabetes

Prognostic Model; Derivation Cohort Characteristics; Size | Validation | Validation Cohort Size (n); Characteristics | Outcome Predicted | Prediction Horizon | Discrimination; C- or AUC Statistic (95% CI) | Calibration Slope^1^ (Observed/Predicted) (95% CI)
Boyko et al (2006); 95% type 2 DM^2^; n=1285 | Internal (development cohort) | 1285; Veterans in the US, 95% with type 2 DM seen in primary care clinics, 98% male | DFU | 1 year | 0.81 (NR) | NA
Boyko et al (2006); 95% type 2 DM^2^; n=1285 | Internal (development cohort) | 1285; Veterans in the US, 95% with type 2 DM seen in primary care clinics, 98% male | DFU | 5 years | 0.76 (NR) | NA
Boyko et al (2006); 95% type 2 DM^2^; n=1285 | External | 7624; Patients in Netherlands with type 2 DM seen in primary care clinics, 53% male | DFU | 5 years | 0.81 (0.75, 0.86) | NA
Martin-Mendes et al; original (2014); 98% type 2 DM; n=644 | Internal (development cohort) | 644; Patients in Portugal, 98% with type 2 DM seen in DM foot clinics, 47% male | DFU | 3 years | 0.8 (0.76, 0.84) | NA
Martin-Mendes et al; original (2014); 98% type 2 DM; n=644 | Internal (development cohort) | 644; Patients in Portugal, 98% with type 2 DM seen in DM foot clinics, 47% male | Amputation | 3 years | 0.83 (0.78, 0.89) | NA
Martin-Mendes et al; original (2014); 98% type 2 DM; n=644 | External | 7624; Patients in Netherlands with type 2 DM seen in primary care clinics; 53% male | DFU^3^ | 5 years | 0.78 (0.73, 0.82) | 1.56 (NR)
Martin-Mendes et al; original (2014); 98% type 2 DM; n=644 | External | 7624; Patients in Netherlands with type 2 DM seen in primary care clinics; 53% male | Amputation | 5 years | 0.81 (0.74, 0.88) | 1.26 (NR)
Martin-Mendes et al; simplified (2014); 98% type 2 DM; n=644 | Internal (development cohort) | 644; Patients in Portugal, 98% with type 2 DM seen in DM foot outpatient clinic, 47% male | DFU | 3 years | 0.79 (0.76, 0.83) | NA
Martin-Mendes et al; simplified (2014); 98% type 2 DM; n=644 | Internal (development cohort) | 644; Patients in Portugal, 98% with type 2 DM seen in DM foot outpatient clinic, 47% male | Amputation | 3 years | 0.81 (0.74, 0.87) | NA
Martin-Mendes et al; simplified (2014); 98% type 2 DM; n=644 | External | 7624; Patients in Netherlands, 100% type 2 DM seen in primary care clinics, 53% male | DFU | 5 years | 0.77 (0.72, 0.82) | 0.97 (NR)
Martin-Mendes et al; simplified (2014); 98% type 2 DM; n=644 | External | 7624; Patients in Netherlands, 100% type 2 DM seen in primary care clinics, 53% male | Amputation | 5 years | 0.78 (0.71, 0.84) | 1.41(NR)
PODUS (2020); type 1 and 2 DM; n=8255 | Internal (development cohort) | 8255; Patients from 4 cohorts in Europe and US with type 1 or 2 DM seen in primary and secondary foot clinics, 53% male | DFU | 2 years | NA | NA
PODUS (2020); type 1 and 2 DM; n=8255 | External | 3324; Patients in UK with type 1 or 2 DM, 91% type 2 DM seen in primary and secondary foot clinics, 57% male | DFU | 2 years | 0.83 (0.79-0.87) | 1.14 (0.99-1.28)

1 Prior to recalibration;

2 Diabetes mellitus;

3 The model of Martins-Mendes et al (original) for predicting DFU used physical impairment as a predictor. Since this variable was not available in the external validation cohort, validation was conducted with the assumption that none of the participants were physically impaired.

Table 6 Variables Included in Prognostic Models Predicting Diabetic Foot Ulcer Development or Amputation in Patients with Diabetes

Prognostic Models (Outcome) | Foot-related Variables | | | | | Non-foot Related Variables | | | | #Variables
Prognostic Models (Outcome) | Neuropathy^1^ | PAD^2^ | Prior DFU | Prior Amputation | Fungal Infection^3^ | Diabetes Complications^4^ | Poor Vision^5^ | Physical Impairment | HbA1c | #Variables
Boyko et al (2006) (DFU) | ✓ | | ✓ | ✓ | ✓ | | ✓ | | ✓ | 7
Martin-Mendes et al original (2014) (DFU) | | ✓ | ✓ | | | ✓ | | ✓ | | 4
Martin-Mendes et al original (2014) (amputation) | | ✓ | ✓ | | | ✓ | | | | 3
Martin-Mendes et al simplified model (2014) (DFU or amputation) | | | ✓ | | | ✓ | | | | 2
PODUS (2020) (DFU) | ✓ | ✓ | ✓ | ✓ | | | | | | 3

1 Assessed as insensate to 10-g monofilament

2 Peripheral arterial disease assessed by absence of at least one pedal pulse

3 Includes evaluation for tinea pedis and onychomycosis

4 Includes evaluation for the total number of diabetes complications, which include retinopathy, nephropathy, neuropathy, cerebrovascular, cardiovascular, peripheral arterial disease, and metabolic (ketoacidosis, hyperosmolar coma, or other coma)

5 Vision poorer than 20/40

## KEY QUESTION 2 What is the effectiveness or comparative effectiveness of orthotic or pedorthic interventions to prevent diabetic foot ulcers?

### Overview

Eighteen SRs were identified that evaluated the effectiveness of interventions for prevention of DFU, 1 of which was an overview of reviews published in 2020 as a Health Technology Assessment for the National Institute for Health Research that informs NICE guidance. Due to the overlapping and large volume of literature, we based our conclusions on the overview of reviews and 3 SRs published after the overview. The eligibility criteria of the included SRs did not always line up entirely with our criteria, and several of the SRs included studies with populations, comparators, and outcomes not relevant to our review (Supplemental Table 4 and Supplemental Table 5)

### Crawford et al 2020 Health Technology Assessment

The review of reviews by Crawford et al identified 20 SRs that evaluated interventions to prevent DFUs in primarily diabetic populations.^11^ The individual SRs included in the overview provided a narrative summary of the effectiveness of various interventions, and some SR authors suggested that there may be some benefit in therapeutic footwear to prevent recurrent ulcers, while other SR authors concluded that there was too much uncertainty in the published literature to provide definitive conclusions and underscored the need for more rigorous studies.^11^

The overview included SRs that specified primary studies of RCTs and observational study design with half of the identified reviews only including RCTs. The Crawford overview scope was broader than our overview scope, as it allowed for any intervention of diabetic foot risk and captured all the previous reviews that our search identified. Interventions were categorized as simple or complex; orthotics were classified as simple interventions (eg, pressure-distributing insoles or bespoke footwear or education packages in relation to foot care or other aspects of self-management aimed at patients or health care professionals). Four SRs included in the overview were deemed to have low ROB in all 4 ROBIS domains. The other 16 included reviews had at least 1 ROBIS domain that had been identified as high ROB. The authors provided a summary table of the included SRs describing the population, intervention, study level conclusions, and synthesis methodology as well as a narrative summary of a subset of reviews for each intervention group. Under the footwear and offloading subheading, the authors narratively summarize the findings from 5 SRs and 1 SR update that captured evidence related to therapeutic footwear or offloading. Under the subheading mixed interventions, 6 SRs were included; these mixed interventions included the use of orthotic or therapeutic footwear in concert with other interventional approaches (eg education, podiatric care). Crawford et al concluded that while the 20 reviews did not all share identical scope, there was sufficient overlap of interventions and populations to warrant inclusion in the overview.

The Crawford overview made the following major conclusions: (1) the majority of SRs provided inconclusive evidence and more primary research is required; (2) the large number of available SRs lends support to the hypothesis that interventions for DFU are regarded with a high degree of clinical uncertainty and there is a desire for more high-quality evidence; (3) conducting a new SR to obtain estimates of effect of interventions on a broad population of people with diabetes was warranted.^11^ Many of the SRs included in the overview were published prior to the Preferred Reporting Items for Systematic Reviews and Meta-Analyses (PRISMA) statement. Thus, earlier SRs may be more likely to be assigned higher ROB as standard features of a review publication were missing.

### Recent Systematic Reviews

Three SRs were published at or slightly after the publication of the aforementioned review of reviews. One is the follow-up SR by Crawford et al in response to their overview of reviews conclusion. Of the 3 reviews, 2 were low ROB and the third was moderate ROB. The 3 SRs included many of the same studies, with 6 of the 7 studies identified by Crawford et al^23^ appearing in van Netten et al^22^ and Alahakoon et al^28^ (Supplemental Table 4 and Supplemental Table 5).

#### Crawford et al 2020

The updated SR by Crawford et al (2020) evaluated the effectiveness of interventions to prevent foot ulceration in people with diabetes.^23^ Unlike the overview of reviews, the SR included only RCTs, whereas the overview allowed for SRs that included non-RCTs. The authors identified 8 intervention categories: 1) education alone; 2) dermal infrared thermometry; 3) complex interventions; 4) custom-made footwear and offloading insoles; 5) digital silicone device; 6) antifungal treatment; 7) elastic compression stockings; and 8) podiatric care. The authors identified 22 RCTs, 6 of which evaluated custom-made footwear and offloading insoles. Based on a pooled estimate, authors found that custom footwear (offloading) versus standard of care or non-therapeutic footwear in those without currently existing DFU reduced the development of DFU (RR = 0.53, 95% CI (0.33, 0.85), I^2^ = 78%) over a 12-24-month time period. However, in a subgroup analysis including only individuals with a prior history of foot ulceration, the pooled effect was less and not statistically significant (RR = 0.77, 95% CI (0.47, 1.06)). Crawford et al concluded: “The meta-analyses of dermal infrared thermometry, complex interventions and therapeutic footwear with offloading insoles suggest that these interventions can help prevent foot ulceration in people with diabetes.” The authors noted several limitations of previous studies examining this intervention, including lack of standardization in terminology, prescription, manufacture, and material properties of interventions; heterogeneity in study designs, methodology and participant populations; and differences in participant characteristics.^23^

#### van Netten et al 2020

van Netten et al (2020) identified 81 publications, 35 studies that had a controlled study design and 46 that had a noncontrolled study design, which investigated the effectiveness of interventions to prevent first and recurrent DFUs.^22^ The authors created 8 intervention categories: 1) foot self-care; 2) structured education about foot self-care; 3) foot self-management; 4) treatment of risk factors or pre-ulcerative signs on the foot; 5) orthotic interventions; 6) surgical interventions, 7) foot-related exercises; and 8) integrated foot care. The primary outcomes of interest were occurrence of first foot ulcer and recurrent ulcer. Seven RCTs, 3 cohort studies, and 9 noncontrolled studies were included under the orthotic intervention category. The authors made the following 2 statements: 1) “In people with diabetes with moderately increased risk for foot ulceration (International Working Group for Diabetic Foot (IWGDF) risk 2), therapeutic footwear, including shoes, insoles, or orthoses, may reduce the risk of a first-ever foot ulcer” (low certainty of evidence); and 2), “In people with diabetes at high risk for foot ulceration (IWGDF risk 3), therapeutic footwear, including custom-made shoes or insoles with a demonstrated plantar pressure-reducing effect on the plantar surface of the foot during walking, and that the patient actually wears, reduces the risk of a recurrent plantar diabetic foot ulcer” (van Netten et al assessed as moderate certainty of evidence).^22^

#### SR Alahakoon et al 2020

Alahakoon et al (2020) was a moderate ROB SR, including 17 RCTs and comparing home foot temperature monitoring, patient education, and foot offloading to prevent DFU.^28^ The authors defined footwear as any shoe or insole designed to relieve mechanical pressure from specific regions of the foot. The primary outcome was diabetes-related foot ulcer incidence. Seven RCTs assessed the use of footwear in preventing DFUs. Offloading footwear reduced the incidence of diabetes-related foot ulcers (OR = 0.48, 95% CI (0.29, 0.80), p = 0.005); I^2^ = 72%. Results were consistent for custom-made orthoses/footwear interventions (OR = 0.47, 95% CI (0.27, 0.82), p = 0.008). The authors concluded that offloading footwear is effective in reducing the incidence of diabetes-related foot ulcers.^28^ However, the high ROB, as assessed by Alahakoon et al, of the included studies reduces certainty of conclusions.

## KEY QUESTION 3 What is the effectiveness or comparative effectiveness of orthotic or pedorthic interventions to treat diabetic foot ulcers?

### Overview

Ten reviews were eligible for inclusion for KQ3. We summarize the findings from the 2 most recent low ROB reviews.^35,38^ The two SRs captured 6 of the same studies in their included citations, though both included more than 6 studies (Supplemental Table 6 and Supplemental Table 7).

### Lazzarini et al 2020

The SR by Lazzarini et al was an update of a previous review and investigated the effectiveness of offloading interventions to heal DFUs.^35^ This review also incorporated the findings from 2 other reviews published after 2016 that we included in our overview.^37,39^ The authors created 4 offloading intervention categories: 1) offloading devices (any offloading intervention that was a custom made or prefabricated device, excluding footwear); 2) footwear (any offloading intervention that was shoe gear, including insoles and socks; 3) other offloading techniques (any other non-surgical offloading intervention that was not an offloading device or footwear); and 4) surgical offloading techniques. The review authors identified a total of 165 publications, including 6 meta-analyses, 39 controlled trials, and 120 non-controlled trials. Twenty citations were identified under the footwear intervention, with 2 meta-analyses, 2 controlled trials, and 16 non-controlled trials. The 2 meta-analyses identified for inclusion under the footwear trials were 2 reviews identified during our search of the literature.^37,39^ Lazzarini et al defined therapeutic footwear as being custom-made or customized footwear with or without insoles. No definition for foot ulcer was provided. Results were summarized narratively, with the following evidence statement: “Therapeutic footwear is less effective than non-removable knee-high offloading devices to heal a neuropathic plantar forefoot or midfoot DFU.” The authors chose to downgrade the certainty of evidence rating to moderate, citing minor inconsistencies among the meta-analyses and RCT findings. The authors concluded the following: “As a result of these findings, conventional or therapeutic footwear should not be used to heal a plantar forefoot or midfoot DFU as there are more effective offloading device interventions available.”^35^

### Healy et al 2018

The SR by Healy et al summarized RCTs assessing the effectiveness of prosthetic and orthotic interventions for DFUs, but the review was not limited to diabetic populations or interventions of the foot.^28^ Orthotic devices/products were defined as “an externally applied device that was used to modify the structural and functional characteristics of the neuromuscular and skeletal systems.” The authors identified 346 RCTs, 15 categorized as related to DFU treatment. The authors summarized findings from 7 RCTs that included ulcer healing as a primary outcome, concluding: “When compared to a control condition, orthotic interventions showed some evidence of superior results with lower ulcer incidence/relapse rates. However, when it comes to treating active ulceration, total contact casts (TCCs) show superior results in most of the RCTs. Our findings are in line with previous research in this area.”^28^