# METHODS

## TOPIC DEVELOPMENT

This topic was nominated by the VA National Clinical Orthotic & Prosthetic Program Office. We worked with our Operational Partners and Technical Expert Panel to guide scope refinement and to develop the key questions.

## KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

1) What are the tool performance characteristics (eg, accuracy, external validation, and implementation) of assessment tools that:
  a) Predict development of new diabetic foot ulcers (first or recurrent)?
  b) Prognosticate outcomes of diabetic foot ulcers?
2) What is the effectiveness or comparative effectiveness of orthotic or pedorthic interventions to prevent diabetic foot ulcers?
3) What is the effectiveness or comparative effectiveness of orthotic or pedorthic interventions to treat diabetic foot ulcers?

## CONCEPTUAL FRAMEWORK

We developed the conceptual framework to guide this review of reviews. The framework details how an adult with diabetes may move through the health care system, first capturing the use of prognostic risk assessment tools to prioritize care for those most at risk, followed by prevention, development, and treatment of diabetic foot ulcers with orthotic devices. Specific outcomes of interest for prognostic tools include accuracy (eg, calibration and discrimination) and implementation facilitation and barriers. Briefly, calibration is the ability of the tool to accurately predict the absolute risk level and discrimination is the ability of the tool to discern at which risk level (ie, low to high) an individual should be categorized. For orthotic interventions, the outcomes of interest included ulcer development (both new and recurrent), ulcer healing, time to ulcer healing, and amputation. The specific measures included in the framework are provided in Figure 1 below.

Figure 1 Conceptual Framework

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42021287645).

## DATA SOURCES AND SEARCHES

We searched for peer-reviewed English language systematic reviews from initiation to July 2021 in the following databases: MEDLINE, Embase, and the Cochrane Database of Systematic Reviews. We used Medical Subject Headings (MeSH) and title/abstract terms for diabetic foot ulcers, risk assessment tools, and footwear or orthotics. To supplement the database search, we reviewed reference lists of relevant systematic reviews identified from database searches. The VA ESP and AHRQ EPC programs were also searched for relevant reviews. The detailed search strategy is provided in Appendix A.

## STUDY SELECTION

After duplicates were removed, citations were uploaded into DistillerSR (Evidence Partners, Ottawa, Canada). Eligible populations included adults (≥18 years of age) with diabetes with or without the presence of a foot ulcer. Eligible articles also must address the intervention of interest, a prognostic risk assessment or footwear, specifically orthotics, on ulcer development and healing. Using the established prespecified inclusion and exclusion criteria, titles and abstracts were screened by 2 reviewers for eligibility. Articles included by either reviewer were moved forward to full-text review. At full-text review, 2 individuals decided on inclusion/exclusion by consensus (input from a third reviewer was requested as needed). A list of studies that were excluded at full-text review can be found in Appendix B. The Prevention for Amputation among Veterans Everywhere (PAVE) program was not identified in the literature search; a search of the grey literature was performed identifying a directive and several press pieces for the program.

### Eligibility Criteria

Table 1 Inclusion and Exclusion Criteria

Domain | Inclusion Criteria | | | | Exclusion Criteria
Domain | Key Question 1a | Key Question 1b | Key Question 2 | Key Question 3 | Exclusion Criteria
Population | Those 18 years or older without a foot ulcer | Those 18 years or older with a foot ulcer | Adults (18 years or older) with diabetes who do not have existing foot ulcers | Adults (18 years and older) with diabetes who have foot ulcers | <18 years of age without diabetes
Intervention | Tools to assess risk of (i) developing a diabetic foot ulcer | Tools to assess risk of (ii) amputation in patients with current ulcers | Orthotic or pedorthic interventions to prevent a diabetic foot ulcer | Orthotic or pedorthic interventions to treat a diabetic foot ulcer
Comparator | Any
Outcomes | - Discrimination for (i) development of an ulcer (first or recurrent): (ii) risk for amputation; - Sensitivity, specificity, predictive value, area under the curve (AUC), calibration, discrimination, risk reclassification; - Implementation (metrics include: time to conduct test/tool, training or certification need to conduct test, location of test performance [in office/outpatient], etc.); - External validation | | - Ulcer occurrence; - Amputation; - Cost; - Adherence | - Ulcer healing (complete vs. reduction in size); - Amputation | Plantar pressure
Timing | Any
Setting | Any | | | | Acute care (ie, emergency rooms or institutional settings (eg, nursing homes)
Study Design | Systematic reviews | | | | Study protocols, case studies, editorials, no comparison group

## DATA ABSTRACTION AND ASSESSMENT

Risk of bias (ROB) was assessed using the Risk of Bias in Systematic Review (ROBIS) tool (Appendix C).^8^ The tool is comprised of 3 phases: the first phase assesses the review’s relevance to the key questions, the second phase identifies concerns with the review process, and the third phase judges the ROB for the review. Phase 2 of ROBIS has 4 domains: 1) study eligibility criteria; 2) identification and selection of studies; 3) data collection and study appraisal; and 4) synthesis and findings. Each domain is comprised of several signaling questions, each with 5 response levels: yes, probably yes, probably no, no, and no information. The final response regarding potential bias in each of the 4 domains is then pooled during phase 3 to assign an overall ROB assessment (low, unclear, or high) to the review. We assigned the term moderate to describe unclear ROB to provide clarity in level of bias. Because some eligible reviews were qualitative in nature, we modified this tool to include a response of not applicable for 2 of the signaling questions under data collection and study appraisal. Any study rated low ROB in all domains was considered low ROB overall. Any study rated as high ROB in 2 or more domains was considered high ROB overall. Any study that did not fulfill either of the 2 previous requirements was considered moderate or unclear ROB overall. Ratings for eligible studies can be found in Appendix C. ROB was assessed by 1 reviewer and confirmed by a second reviewer. Reconciliation was reached via discussion and a third reviewer if necessary.

We abstracted data from eligible reviews rated as low or moderate ROB. Data were abstracted by 1 person and confirmed by a second. If needed to resolve conflicts, a third reviewer also evaluated the study. As many of the reviews were narrative reviews, we abstracted data on study and population characteristics, including sample size, number of studies, search strategy, setting (regional vs national US), inclusion and exclusion criteria, interventions, comparators, and outcomes (eg, ulcer development, ulcer healing, amputation). For outcomes, we abstracted review characteristics, measurements captured in the reviews, and the review authors’ conclusions and limitations.

Each of the tools identified in the reviews relevant to KQ1 were noted. A review of the primary literature was then performed for the tools identified as top performers by the systematic reviews. Tools were categorized as (i) risk classification systems if they classified level of risk (eg, high or low) without an absolute outcome rate over a specified time horizon; (ii) prognostic models if they classified level of risk over a specified time horizon, but did not describe absolute outcome rates; and (iii) prediction tools if they predicted absolute outcome rates over a specified time horizon. Performance metrics for these top tools were identified and abstracted from the primary literature when available.

Specific outcomes of interest for prediction models and tools were prognostic accuracy and implementation characteristics. Measures of prognostic accuracy assessed were calibration and discrimination. Calibration measures how accurately the model’s predictions match overall observed event rates. Calibration was evaluated using calibration plots and the observed/predicted ratio. An observed/predicted ratio of close to 1 supports an overall good calibration, and calibration plots enable an assessment for how predicted rates match observed rates across all levels of absolute predicted risk.^9^ Discrimination refers to the ability of the model to separate individuals who will develop events from those who will not.^9^ Discrimination is evaluated using a C statistic or area under the curve for the receiver operating curve (AUC-ROC); both of which are measures of concordance. C statistics generally range from 0.5 (random concordance) to 1 (perfect concordance). A C statistic value of 0.5-0.6 is poor, 0.6-0.7 is fair, 0.7-0.8 is good, and >= 0.8 is excellent discrimination. C statistics measure the ability of a model to rank patients from high to low risk but do not assess the ability of a model to assign accurate probabilities of an event occurring (that is measured by the model’s calibration). Prognostic accuracy was evaluated in internal or external validation studies. Validation was referred to as internal when it was done using the original study sample with or without use of methods such as bootstrapping or cross validation. Since internal validation tends to give an optimistic estimate of performance, we also assessed for external validation, defined as assessing prognostic accuracy of prediction models in a cohort independent of the development cohort.^10^ We also qualitatively assessed implementation for prediction models based on measures likely to enhance implementation feasibility in primary care clinics (the health care setting where most diabetic foot ulcer prognostic tools would be used). Factors included number of items in the tool, ability to readily collect by history, clinical examination, laboratory value information on individual patients at the point of patient-clinician contact, time to complete, and ease of calculating a final prognostic score.

For both KQ 2 and 3, our search identified recently published systematic reviews (rated low or moderate ROB) which addressed the questions and captured previous reviews and prior evidence. Since high-quality work already exists in these areas; we summarize these recent reviews and their findings.^11^

## SYNTHESIS

Due to the heterogeneity of identified studies, intervention definition, and the number of existing systematic reviews summarizing prediction tools and interventions for prevention and treatment of diabetic foot ulcers, a narrative synthesis in a review of reviews was developed. We summarize study findings by the key questions and outcomes of ulcer development, healing, or amputation. We subsequently describe in greater detail tools and their results deemed most feasible based on number and type of components as well as ability to implement in a primary care setting. We identified limitations within the reviews, independent of the authors, and provide a summary of the findings and potential.

## PEER REVIEW

A draft version of this report was reviewed by technical experts as well as clinical leadership. Their comments and our responses are presented in Appendix D.