# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) is responding to a request from the VA National Clinical Orthotic and Prosthetic Program Office. Findings from this review will be used to update existing therapeutic footwear policies and guidelines and inform standards of care and care delivery for the assessment and management of Veterans at risk for diabetic foot complications.

## BACKGROUND

An estimated 422 million people worldwide have diabetes, with 1.6 million deaths attributed to diabetes each year.^1^ In 2018, in the United States, an estimated 10.5% (34 million) of the population had diabetes.^2^ In Veterans, the prevalence of diabetes is even higher at 24%.^3^ Patients with diabetes have significant comorbidities and complications, including obesity, cardiovascular disease, peripheral arterial disease, kidney disease, and neuropathy. The likely synergistic effect of these co-existing comorbidities and complications predisposes diabetic patients to an increased risk of developing a diabetic foot ulcer (DFU) with resultant poor outcomes including amputation. About 5% of patients who develop a DFU undergo an amputation within 1 year of diagnosis. Among the nearly 8 million hospital discharges that occurred in 2016 in the US with diabetes listed as any diagnosis, 130,000 were for a lower extremity amputation.^2^ Among veterans with diabetes in 2010, ~3,400 individuals underwent a lower extremity amputation.^4^ Patients with an incident DFU also have exceedingly high 5-year mortality rates likely due to their greater severity of diabetes and higher burden of comorbid conditions, up to 45% in the general population and 60% in Veterans.^5,6^ The development of a DFU and its resultant treatment also results in a significant decrease in patients’ quality of life due to a reduction in physical and social activities.^7^ Lastly, the cost of treating DFUs in the VA is high, exceeding $3 billion annually.^4^ Hence, the development of a DFU is associated with significant morbidity, mortality, decreased quality of life, and increased health care costs.

The VA National Clinical Orthotic and Prosthetic Program Office requested an evidence review of prognostic tools to assess risk of DFU development and outcome, and orthotic and pedorthic interventions to prevent and treat DFUs. A preliminary search of the literature identified more than 10 relevant systematic reviews published in the last 5 years; as such we performed a review of reviews intended to inform (a) the development of protocols for the clinical evaluation of Veterans with diabetes with or without DFUs, and (b) an update of existing therapeutic footwear policies and guidelines. Our review of reviews aimed to answer 2 key questions:

1) What are the tool performance characteristics (eg, accuracy, external validation, and implementation) of assessment tools that:
  a) Predict risk of developing new diabetic foot ulcers (first or recurrent)?
  b) Prognosticate outcomes of diabetic foot ulcers?
2) What is the effectiveness or comparative effectiveness of orthotic or pedorthic interventions to prevent diabetic foot ulcers?
3) What is the effectiveness or comparative effectiveness of orthotic or pedorthic interventions to treat diabetic foot ulcers?

Given the frequency of diabetes and DFUs among Veterans with the resultant poor outcomes, the answers to these questions are of critical importance to the individual, the health care system, and society.