# APPENDIX E SUPPLEMENTAL TABLES

Supplemental Table 1 Description of Prognostic Tools or Models that Predict Diabetic Foot Ulcer (DFU) or Amputation with a Time Horizon For Prediction

Tool | Tool Characteristics
Boyko et al (2006)^42^ | Variables: | HbA1C, vision poorer than 20/40, history of foot ulcer, history of amputation, monofilament insensitivity, tinea pedis, onychomycosis
Boyko et al (2006)^42^ | Model: | A1C × 0.0975 + 0.7101 (neuropathy present) + 0.3888 (poor vision) - 0.3206 (tinea pedis present) + 0.4579 (onychomycosis present) + 0.7784 (past history of foot ulcer) + 0.943 (past history of lower limb amputation)
Boyko et al (2006)^42^ | Outcome Predicted: | DFU
Boyko et al (2006)^42^ | Time Horizon: | 1 and 5 years
Boyko et al (2006)^42^ | Risk Categories: | Quantified by risk score quartiles as below:; Lowest quartile: 0.61-1.47; Second lowest: 1.48-1.99; Second highest: 2.00-2.61; Highest: 2.62-5.07
Martins-Mendes et al [original] (2014)^43^ | Variables: | Physical impairment, PAD complication history, complications count (retinopathy, nephropathy, neuropathy, cerebrovascular, cardiovascular, peripheral arterial disease and metabolic (ketoacidosis, hyperosmolar coma or other coma)), prior DFU
Martins-Mendes et al [original] (2014)^43^ | Model: | -3.29 + 0.55 × Physical impairment + 0.93 × PAD complication history presence + 0.27 × number of complications count + 1.51 × Previous DFU
Martins-Mendes et al [original] (2014)^43^ | Outcome Predicted: | DFU or amputation
Martins-Mendes et al [original] (2014)^43^ | Time Horizon: | 3 years
Martins-Mendes et al [original] (2014)^43^ | Risk Categories: | unclear
Martins-Mendes et al [simplified] (2014)^43^ | Variables: | Complications count (retinopathy, nephropathy, neuropathy, cerebrovascular, cardiovascular, peripheral arterial disease and metabolic (ketoacidosis, hyperosmolar coma or other coma))
Martins-Mendes et al [simplified] (2014)^43^ | Model: | [underlined: Simplified model for predicting DFU]; -2.86 + 0.46 × number of complications* count + 1.84 × previous DFU; [underlined: Simplified model for predicting amputation]; -5.35 + 0.61 × number of complications count + 1.91 × previous DFU
Martins-Mendes et al [simplified] (2014)^43^ | Outcome Predicted: | DFU or amputation
Martins-Mendes et al [simplified] (2014)^43^ | Time Horizon: | 3 years
Martins-Mendes et al [simplified] (2014)^43^ | Risk Categories: | unclear
PODUS 2020^46^ | Variables: | Neuropathy, PAD, history of DFU or lower-extremity amputation
PODUS 2020^46^ | Model: | Quantifies risk with total potential scores 0 to 4 using the sum of:; Score 1 if insensitive to a 10 g monofilament.; Score 1 if any pedal pulse is absent (dorsalis pedis and posterior tibial pulses on both feet); Score 2 if there is history of previous ulcer or amputation.
PODUS 2020^46^ | Outcome Predicted: | DFU
PODUS 2020^46^ | Time Horizon: | 2 years
PODUS 2020^46^ | Risk Categories: | Score 0—average risk is 2.4% (95% CI 1.4% to 3.9%) at 2 years; Score 1—average risk is 6.0% (95% CI 3.5% to 9.5%) at 2 years; Score 2—average risk is 14% (95% CI 8.5% to 21%) at 2 years; Score 3—average risk is 29% (95% CI 19% to 41%) at 2 years; Score 4—average risk is 51% (95% CI 38% to 64%) at 2 years

DFU: diabetic foot ulcer

Supplemental Table 2 Description of Risk Classification Tools or Models that Predict Diabetic Foot Ulcer (DFU) Development or Amputation without a Time Horizon

Tool | Tool Characteristics
PODUS 2015 | Variables: | Neuropathy, PAD, history of DFU or lower extremity amputation
PODUS 2015 | Model: | -
PODUS 2015 | Outcome Predicted: | DFU
PODUS 2015 | Time Horizon: | Unclear
PODUS 2015 | Risk Categories: | Moderate risk: neuropathy or PAD; High risk: patient’s history of DFU or amputation
Queensland High Risk Foot Form (QHRFF) tool | Variables: | Foot deformity, neuropathy, PAD, previous ulcer or amputation
Queensland High Risk Foot Form (QHRFF) tool | Model: | -
Queensland High Risk Foot Form (QHRFF) tool | Outcome Predicted: | DFU
Queensland High Risk Foot Form (QHRFF) tool | Time Horizon: | Unclear
Queensland High Risk Foot Form (QHRFF) tool | Risk Categories: | Low risk: No neuropathy or PAD; At risk: Neuropathy or PAD; High risk: foot deformity with neuropathy and/or PAD or previous ulcer or amputation or critical PAD
Prevention of Amputation in Veterans Everywhere (PAVE) | Variables: | Neuropathy, PAD, specified deformity (bunion, hammertoe, claw toe, mallet toe, metatarsal head deformity, etc), prior DFU/osteomyelitis/amputation, intermittent claudication/rest pain, gangrene/peripheral bypass surgery/angiography, ESRD
Prevention of Amputation in Veterans Everywhere (PAVE) | Model: | -
Prevention of Amputation in Veterans Everywhere (PAVE) | Outcome Predicted: | Unclear
Prevention of Amputation in Veterans Everywhere (PAVE) | Time Horizon: | Unclear
Prevention of Amputation in Veterans Everywhere (PAVE) | Risk Categories: | 0 Normal risk: Diabetes with no other problems; 1 Low risk: Diabetes with minor deformity; 2 Moderate risk: Diabetes with diminished circulation (but not diagnosed PAD) and/or sensory neuropathy with or without deformity; 3 Highest risk: Diabetes with diagnosed PAD, with or without sensory neuropathy and any patient who has end stage renal disease, diagnosed PAD, Charcot foot, past history of gangrene, foot ulceration or amputation

DFU: Diabetic foot ulcer; PAVE: Prevention of Amputation in Veterans Everywhere

Supplemental Table 3 Description of Risk Classification Tools that Predict Outcome of DFU without a Time Horizon

Tool | Tool Characteristics
Perfusion, Extent, Depth, Infection, and Sensation (PEDIS) | Variables: | Perfusion (palpation of pedal pulses and non-invasive vascular studies), extent (ulcer area), depth, infection (evaluation for symptoms and signs of inflammation), sensation (loss of sensation to monofilament and/or vibration)
Perfusion, Extent, Depth, Infection, and Sensation (PEDIS) | Model: | -
Perfusion, Extent, Depth, Infection, and Sensation (PEDIS) | Outcome Predicted: | Healed, unhealed, amputation, or death
Perfusion, Extent, Depth, Infection, and Sensation (PEDIS) | Time Horizon: | Unclear (ranged from 6 to 82 months)
Perfusion, Extent, Depth, Infection, and Sensation (PEDIS) | Risk Categories: | See Chuan et al
Site, Ischemia, Neuropathy, Bacterial Infection, Area, and Depth score (SINBAD) | Variables: | Site of DFU (forefoot or midfoot/hindfoot), ischemia (palpation of pedal pulses), neuropathy (loss of sensation to monofilament), bacterial infection, area (<1cm^2^ or ≥1cm^2^), depth of ulcer
Site, Ischemia, Neuropathy, Bacterial Infection, Area, and Depth score (SINBAD) | Model: | -
Site, Ischemia, Neuropathy, Bacterial Infection, Area, and Depth score (SINBAD) | Outcome Predicted: | Time to healing
Site, Ischemia, Neuropathy, Bacterial Infection, Area, and Depth score (SINBAD) | Time Horizon: | Unclear
Site, Ischemia, Neuropathy, Bacterial Infection, Area, and Depth score (SINBAD) | Risk Categories: | See Ince et al

DFU: diabetic foot ulcer; PEDIS: Perfusion, Extent, Depth, Infection, and Sensation; SINBAD: Site, Ischemia, Neuropathy, Bacterial Infection, Area, and Depth score (SINBAD)

Supplemental Table 4 Characteristics and Results for Systematic Reviews Relevant to KQ2

Author (year); Search Dates (sources); ROBIS Rating | Population | Synthesis Method; Included Study Design; Number of Studies | I (Intervention)/C (Comparators) | Outcomes Assessed | Review Author Conclusions
Review of Reviews
Crawford (2020a)^11^; Inception – February 2019; (Medline, Embase, Cochrane); LOW | Adults with a diagnosis of diabetes mellitus, either type 1 or type 2 | Qualitative; RCT and observational; 20 systematic reviews | I: Simple interventions (eg, pressure-distributing insoles or bespoke footwear or education packages in relation to foot care or other aspects of self-management aimed at patients or health-care professionals) or complex interventions (eg, care from a specialist multidisciplinary team in which several interacting interventions were evident) were considered for inclusion in the review.; C: standard care or active comparators, including simple and complex interventions | Absolute number of incident ulcers; absolute number of recurrent ulcers; time to ulceration; quality of life | Although no robust pooled estimates of effect were identified, the majority of SRs by researchers globally to identify preventative interventions for DFUs reflects the high degree of clinical uncertainty among those delivering care and a clear desire to establish an evidence-based approach for the prevention of foot ulcers.; The authors concluded conducting a new systematic review of interventions to prevent ulcer and re-ulcer was warranted.
Systematic Reviews
van Netten (2020)^22^; Inception – July 24, 2018 (PubMed, Embase, CINAHL, Cochrane); LOW | Adults at risk for foot ulceration, defined according to the IWFDF risk stratification as “people with diabetes mellitus and peripheral neuropathy.” | Qualitative; RCT and observational: 35 controlled, 46 non-controlled | I:; 1. Foot self-care; 2. Structured education about foot self-care; 3. Foot self-management; 4. Treatment of risk factors or pre-ulcerative signs on the foot; 5. Orthotic interventions; 6. Surgical interventions; 7. Foot-related exercises; 8. Integrated foot care; C: any | Primary: first ever diabetic foot ulcer and recurrent diabetic foot ulcer; Secondary: lower-extremity amputation, ulcer severity, ulcer-free survival days, heal-related quality of life, and financial costs | Evidence Statement:; Orthotic interventions:; “In people with diabetes with moderately increased risk for foot ulceration (IWGDF risk 2), therapeutic footwear, including shoes, insoles or orthoses, may reduce the risk of a first-ever foot ulcer.” LOW* quality of evidence; “In people with diabetes at high risk for foot ulceration (IWGDF risk 3), therapeutic footwear, including custom-made shoes or insoles with a demonstrated plantar pressure-reducing effect on the plantar surface of the foot during walking, and that the patient actually wears, reduces the risk of a recurrent plantar diabetic foot ulcer.” MODERATE* quality of evidence (this was reduced from high to moderate as the findings between RCTs were inconsistent (CIs cross the 0 line), and there were large confidence intervals around the effect found (imprecision).); *GRADE certainty of evidence statements
Crawford (2020b)^23^; Inception – February 2019; OVID MEDLINE and OVID EMBASE, and Cochrane Central Register of Controlled Trials; LOW | Adults with a diagnosis of type 1 or type 2 diabetes, with or without a history of ulceration, but free from foot ulceration at trial entry | Quantitative and qualitative; RCT only; 22 | I: Digital silicone devices-further defined as bespoke silicone digital orthotics, custom made footwear and offloading insoles (not defined) including cork insoles, and elastic compression stockings; C: a control group not receiving the intervention under study | Presence of incident, primary or recurrent foot ulcers, absolute numbers of incident primary ulcers and of incident recurrent ulcers | Twenty-two RCTs of 8 interventions were eligible for analysis. One trial of digital silicone devices (RR 0.07 [95% CI 0.01, 0.55]) and meta-analyses of dermal infrared thermometry (RR 0.41 [95% CI 0.19, 0.86]), complex interventions (RR 0.59 [95% CI 0.38, 0.90], and custom-made footwear and offloading insoles (RR 0.53 [95% CI 0.33, 0.85]; 6 RCTs) showed beneficial effects for these interventions.; Conclusion: Four interventions were identified as being effective in preventing foot ulcers in people with diabetes, but uncertainty remains about what works and who is most likely to benefit.
Alahakoon (2020)^28^; Inception – October 11, 2019; Medline, PubMed, CINAHL, Scopus, and Cochrane; MODERATE | Participants had diabetes and were all at risk of developing a diabetic foot ulcer (IWGDF risk category 2 or 3) | Quantitative; RCT only; 17 RCTs | I: Home foot temperature monitoring, education of the person with diabetes, or offloading footwear; C: a control group not receiving the intervention under study | Development of foot ulcer | The main meta-analysis suggested that offloading footwear reduced the incidence of diabetes-related foot ulcers (OR 0.48, 95% CI 0.29 to 0.80; p= 0.0005). Heterogeneity among studies was moderate (I^2^ = 72%).; A subgroup meta-analysis was also eligible and suggested that custom-made orthoses/footwear reduced diabetes-related foot ulcer incidence (OR 0.47, 95% CI 0.27 to 0.82; p =0.0008) despite moderate heterogeneity (I^2^ = 70%).; The meta-analysis suggests that offloading footwear is effective at reducing the incidence of diabetes-related foot ulcers.
Heuch (2016)^29^; Inception – November, 2013; (PubMed, Cochrane, CINAHL, EMBASE, SCOPUS, and Google Scholar); MODERATE | Adults with diabetes mellitus, regardless of age, gender, ethnicity, duration or type of diabetes, with no history of DFUs and in any clinical setting | Qualitative; RCT and observational; 3 | I: All offloading methods, including, but not limited to padding (in-shoe and attached directly to the foot), customized insoles, customized orthotic devices, and customized footwear; C: any | Foot ulceration (primary) | There is limited and low-quality evidence that in a population of adults with diabetes with no history of DFU, the use of footwear with customized or prefabricated orthotic devices may provide some reduction in plantar pressure and therefore help to prevent a primary DFU. There is a lack of evidence on the relative effectiveness of different offloading options.
van Netten (2016)^24^; Inception – July 24, 2014; (PubMed, Embase, CINAHL, and Cochrane); LOW | Persons with type 1 or 2 diabetes mellitus who are at risk for foot ulceration | Qualitative; RCTs and observational; 30 RCTs, 44 uncontrolled | I:; 1. Care; 2. Self-management; 3. Medical; C: any | First and recurrent diabetic foot ulcer | Studies on the specific role of therapeutic footwear in preventing a first foot ulcer in at-risk individuals with diabetes are lacking and are therefore urgently needed.; Several recently published high-quality RCTs indicate that specific modalities of therapeutic footwear can be effective in the prevention of a recurrent plantar foot ulcer compared with more standard of care therapeutic footwear.; This systematic review of the literature shows that the evidence base to support the use of interventions that aim to prevent a first foot ulcer in the at-risk patient with diabetes is practically nonexistent. More data are available on the prevention of a recurrent foot ulcer, with strong evidence supporting the home monitoring of foot skin temperatures with subsequent preventative actions and the use of therapeutic footwear with demonstrated pressure-relieving effect that is consistently worn by the patient.
Jarl (2016)^32^; Inception – June, 2016; (Pubmed, CINAHL, and PsychINFO); HIGH | Patients with diabetes with a healed ulcer | Qualitative; observational only; 6 studies | I: Therapeutic footwear; C: any | Adherence | There are too few studies to draw any definitive conclusions about factors associated with adherence to wearing therapeutic shoes.
Bus (2015)^12^; May 1, 2006 – July 29, 2014 (PubMed, EMBASE, CINAHL, Cochrane, Database of Abstracts of Review of Effect, Central Register of Controlled Trials, National Health Service Economic Evaluation Database, Health Technology Assessment Database); LOW | Patients with diabetes mellitus type 1 or 2, and clinical problem addressed was a foot ulcer | Qualitative; RCT and observational; 2 systematic reviews, 20 RCTs, 4 other controlled studies, 54 non-controlled studies | I:; 1. Casting; 2. Footwear; 3. Surgical offloading; 4. Other offloading techniques; C: any offloading technique or standard or care | Ulcer prevention and the reduction of mechanical pressure | The evidence base to support the use of interventions that prevent a first foot ulcer and prevent or heal non-plantar foot ulcers or ischemic or infected ulcers is practically non-existent.
Healy (2013)^25^; Inception – December 2012; (CINAHL, Medline and Cochrane); LOW | Participants had diabetes (type 1 or 2) | Qualitative; RCT and observational; 14 studies | I: Footwear; C: standard care or a control group | Ulceration or reulceration | No research to date has examined the effectiveness of footwear in preventing ulceration and the effectiveness of footwear interventions to prevent reulceration is conflicting. Results from cross-sectional studies support the use of rocker sole footwear and custom orthoses in plantar pressure reduction; however, the effect of orthoses in ulceration prevention needs to be verified through longitudinal studies. Additionally, generic recommendations on these features are not possible as the optimal design will be patient specific.; Conflicting results on the effectiveness of footwear in preventing ulcer relapse are present in the literature. In addition to providing information on ulceration rates, it would be beneficial if future studies provided information on the location of the ulcers. This would allow researchers to assess the relationship between the footwear intervention and the development of the ulcer.
Hunt (2011)^13^; Inception – September 2010; (Medline, Embase and Cochrane); HIGH | People with diabetes, with and without an ulcer | Qualitative; RCT and observational; 50 SRs and RCTs – 2 studies (1 RCT and 1 observational relevant to KQ2) | I: Interventions to prevent or treat foot ulcers and amputations; C: usual footwear | Ulcer development rates, amputation rates, ulcer healing rate, infection rates, and adverse effects | We don’t know whether therapeutic footwear is more effective at reducing the incidence of foot ulcers after 1 to 2 years in people without severe foot deformity (low-quality evidence).; Individuals with significant foot deformities (such as hammer toes or Charcot foot) should be considered for referral for assessment for customized shoes that can accommodate the altered foot anatomy. In the absence of significant deformities, high-quality well-fitting non-prescription footwear seems to be a reasonable option.
Paton (2011)^26^; Inception – 2008; (Medline and CINAHL); LOW | People with diabetes (type 1 or 2) with neuropathy | Qualitative; RCT and observational; 5 studies | I: footwear; C: standard of care or usual footwear | Ulceration and time to ulceration | Insoles designed to prevent ulceration in the diabetic neuropathic foot appear to be of some value and should be considered within the prevention strategy for the diabetic neuropathic foot. Recommendation cannot be made at this time regarding the type and specification of insoles best suited for purpose.; There is a need for further research investigating the following:; 1) comparison of a range of insoles with differing mode of action; 2) comparison of pre-fabricated and custom-made insoles; 3) longevity of devices; 4) economic evaluation of insoles; 5) effectiveness of insoles specific to (neuropathic) foot pathology; 6) patient perception of changes in foot health and quality of life.; Within the limitations of the current evidence, insoles are effective in reducing ulceration rate and peak pressure in people with diabetes and neuropathy.
Aard (2011)^30^; January 1, 1960 – April 30, 2010; (Medline and PubMed); MODERATE | Subjects deemed at risk of diabetic foot ulcers | Qualitative; RCTs and observational; 12 RCTs | I: Therapeutic shoes; insole inserts; shear-reducing insole; C: any | Ulceration and recurrent ulceration | On the basis of our review, the evidence for most of the interventions to prevent a foot ulcer falls short.; Although the data do not support the use of therapeutic shoes or vertical stress-reducing insoles, shear stress-reducing insoles seem more promising.
Bus (2008)^14^; Inception – May 1, 2006; (Medline, Embase, CINAHL, Cochrane, DARE, EED, and HTA); LOW | Patients with type 1 or 2 diabetes, with or without a foot ulcer | Qualitative; RCT and observational; 21 controlled, 108 uncontrolled/cross-sectional | I:; 1. Casting techniques; 2. Footwear-related techniques; 3. Surgical offloading techniques; 4. Other offloading techniques; C: any | Ulcer prevention | No experimental studies exist on the role of footwear and offloading in primary ulcer prevention. There are indications that therapeutic shoes may be effective in secondary prevention compared to standard footwear, although one RCT has found no effect.
Singh (2005)^33^; January 1980 – April 2004; (EBSCO, MEDLINE, and National Guideline Clearinghouse); HIGH | Patients at risk for diabetic foot ulcer | Qualitative; RCT and observational; 165, 22 RCTs (4 studies related to KQ2) | I: Educational, clinical, custom footwear and orthotics, debridement, foot specialist and multidisciplinary team care, prophylactic foot surgeries; C: any | Ulcer recurrence | The value of prescription footwear for ulcer prevention is unclear.
O’Meara (2000)^27^; Inception – December 1998; (19 databases including MEDLINE, CINAHL, British Diabetic Foot Association); LOW | Patients with foot ulcers resulting from diabetes mellitus | Qualitative; RCT and observational; 39 trials, 2 economic evaluations | I:; 1. Footwear; 2. Hosiery; 3. Education; 4. Screening and foot protection program; 5. Podiatry; C: any | The development and incidence of ulceration; ulcer recurrence rate | A second small trial showed a significant reduction in ulcer recurrence in patients wearing special shoes.; There is weak evidence, from one trial of 69 patients, that molded footwear may influence ulcer recurrence at 12 months.; …the research in the area of prevention and treatment of diabetic foot ulcers is extremely poor quality and relatively uninformative.
Mason (1999)^34^; 1983 – NR; (Cochrane, Medline, Embase, CINAHL, Psyclit, HealthStar, Science Citation Index, and Social Science Citation Index); HIGH | People with type 1 or 2 diabetes | Qualitative; RCT and observational; 2 RCTs | I: Screening, management, prevention or education relating to foot care of people with diabetes; C: any | Ulceration, relapse | This remains a research issue where ‘optimized’ normal shoes could be usefully compared with special therapeutic footwear. Without consideration of this pragmatic alternative and confirmatory studies on larger patient numbers, the relative effectiveness and cost effectiveness of providing therapeutic shoes remains uncertain.
Steed (2006)^15^; NR; ((Previous guidelines, PubMed, Medline, Embase, Cochrane); HIGH | Patients with diabetes | Qualitative; RCT and observational; guideline 2.1 – 7 studies | I: Diagnosis, offloading, infection control, wound bed preparation, dressings, surgery, adjuvant agents (topical, device, systemic), and prevention recurrence; C: any | Ulcer development | Guideline 2.1: Protective footwear should be prescribed in any patient at risk for amputation (significant arterial insufficiency, significant neuropathy, previous amputation, previous ulcer formation, preulcerative callus, foot deformity, evidence of callus formation). (Level II); Principle: The incidence of ulceration in diabetic patients at risk for ulceration can be reduced by using protective footwear; *Level II: Less than Level I, but at least 1 RCT and at least 2 significant clinical series or expert opinion papers with literature reviews supporting the intervention.

DFU: diabetic foot ulcer; RCT: randomized controlled trial; TCC: total contact cast; RCW: removable cast walker

Supplemental Table 5 KQ2 Citation Matrix

Included Studies^*^ | Crawford^51^ | van Netten^22^ | Alahakoon^28^
Bus SA, Waarjman R, Arts M (2013) Effect of custom-made footwear on foot ulcer recurrence in diabetes: a multicenter randomized controlled trial. Diabetes Care 36 (12): 4109–4116 24130357 24130357 | X | X | X
Busche K, Chantelau E. Effectiveness of a brand of stock ‘diabetic’ shoes to protect against diabetic foot ulcer relapse. A prospective cohort study. Diabet Med. 2003 Aug; 20(8):665–669.12873296 | | X
Lavery LA, Lafontaine J, Higgins KR, Lanctot DR, Constantinides G (2012) Shear-reducing insoles to prevent foot ulceration in high-risk diabetic patients. Adv Skin Wound Care 25 (11): 519–524 23080240 | X | X | X
Reiber GE, Smith DG, Wallace C (2002) Effect of therapeutic footwear on foot reulceration in patients with diabetes: a randomized controlled trial. JAMA 287(19): 2552–2558 12020336 | X | X | X
Reike H, Bruning A, Rischbieter E, Vogler F, Angelkort B. Recurrence of foot lesions in patients with diabetic foot syndrome: influence of custom-molded orthotic device. Diabetes Stoffwechsel. 1997;6: 107–113 | | X
Rizzo L, Tedeshi A, Fallani E (2012) Custom-made orthosis and shoes in a structured follow-up program reduces the incidence of neuropathic ulcers in high-risk diabetic foot patients. Int J Low Extrem Wounds 11(1):59–64 22336901 | X | X | X
Scire V, Leporati E, Teobaldi I, Nobili LA, Rizzo L, Piagessi A. Effectiveness and safety of using Podikon digital silicone padding in the primary prevention of neuropathic lesions in the forefoot of diabetic patients. J Am Podiatr Med Assoc. 2009 Jan – Feb; 99(1): 28–34.19141719 | X | X
Uccioli L, Faglia E, Monticone G (1995) Manufactured shoes in the prevention of diabetic foot ulcers. Diabetes Care 18 (10): 1376–1378 8721941 | X | X | X
Ulbrecht JS, Hurley T, Mauger DT, Cavanagh PR (2014) Prevention of recurrent foot ulcers with plantar pressure-based in-shoe orthoses: the CareFUL prevention multicenter randomized controlled trial. Diabetes Care 37(7): 1982–1989.24760263 | X | X | X
Viswanathan V, Madhavan S, Gnanasundaram S, Effectiveness of different types of footwear insoles for the diabetic neuropathic foot: a follow-up study. Diabetes Care 2004 Feb; 27(2):474–477 14747231 | | X
Lopez-Moral M, Lazaro-Martinez JL, Garcia-Morales E, Garcia-Alvarez Y, Alvaro-Afonso FJ, Molines-Barroso RJ. Clinical efficacy of therapeutic footwear with a rigid rocker sole in the prevention of recurrence in patients with diabetes mellitus and diabetic polyneuropathy: a randomized clinical trial. PLoS One 2019; 14:e0219537 31295292 | | | X

* Studies grouped under therapeutic or offloading footwear by review authors

Supplemental Table 6 Characteristics and Results for Systematic Reviews Relevant to KQ3

Author (year); Search Dates (sources); ROBIS Rating | Population | Synthesis Method; Included Study Design; Number of Studies | I/C | Outcomes Assessed | Overall Conclusions
Lazzarini (2020)^35^; July 29, 2014 - August 13, 2018; (PubMed, EMBASE, Cochrane Library); LOW | Patients with a DFU, defined as any full thickness lesion below the malleoli associated with peripheral neuropathy and/or peripheral artery disease in people with diabetes. | Qualitative; RCT and observational; 126 studies | I: any intervention undertaken with the intention of relieving mechanical stress from a specific region of the foot.; C: any | Healed DFU | Nonremovable knee-high offloading devices are more effective than removable offloading devices to heal the DFU – HIGH*; Removable knee-high offloading devices and removable ankle-high offloading devices are equally effective to heal the DFU – MODERATE*; Therapeutic footwear is less effective than non-removable knee-high offloading devices to health the DFU – MODERATE*; Removable knee-high walkers seem to be more cost-effective than therapeutic footwear in healing the DFU. -Low*; Custom-made light-weight fiberglass heel cast in addition to usual care seems to be equally cost effective as using usual care alone in patients with a neuropathic rearfoot DFU. – Low*; * Use of GRADE to determine low, moderate, or high certainty.
Healy (2018)^38^; Inception - September 27, 2015; (Web of Science, Medline, Pubmed, CINAHL Plus, EMBASE, SCOPUS, Rehabdata, PsycInfo, ERIC, Education Research Complete, Business Source Complete, IEEE, NIHR, and CEA registry); LOW | Adults with physical impairments, limb loss, functional limitations or deformities in limb or spine | Qualitative; RCT only; 346 (15 related to DFU) | I: Prosthesis: externally applied device used to replace wholly, or in part, an absent limb or deficient limb segment; C: non-provision of prosthetics or orthotics, provision of prosthetic or orthotic, provision of a non-prosthetic or non-orthotic | Disability adjusted life years (DALY)/qualit y-adjusted life years (QALY); better health outcomes (functioning and quality of life); | When it comes to treating active ulceration, total contact casts showed superior results in most of the RCTs. Our findings are in line with previous research in this area.
Health Quality Ontario_Costa (2017)^39^; Inception - August 17, 2016 (Medline, embase, Cochrane Central Register of Controlled Trials, Cochrane Database of Systematic Reviews, Health Technology Assessment, National Health Service Economic Evaluation Database, and Database of Abstracts of Reviews of Effects, CINAHL); MODERATE | Patients with type 1 or 2 diabetes who had neuropathic infected or noninfected foot ulcers | Quantitative; RCTs only; 13 studies | I: Fiberglass total contact casting; C: other offloading devices: total contact casting prepared using materials other than fiberglass, therapeutic shoes, custom braces, or ankle and foot orthoses nonoffloading ulcer treatments (ulcer dressings) | Ulcer healing time to ulcer healing | Total contact casting versus therapeutic shoes, percentage of healed ulcers; Risk difference Mantel Haenszel fix effects [95%CI]; 0.25 [0.04, 0.46]; Risk Ratio Mantel Haenszel Random [95%CI]; 1.62 [1.11, 2.38]; Our meta-analysis showed a statistically significant improvement in ulcer healing with total contact casting compared with therapeutic shoes within 1 to 4 months of follow-up.; GRADE for evidence profile for total contact casting versus therapeutic shoes:; Moderate for percentage of patients with a healed ulcer; Moderate for time to healing; Removable cast walkers versus therapeutic shoes, percentage of healed ulcers; Risk difference Mantel Haenszel fix effects [95%CI]; −0.13 [−0.31, 0.06]; Risk Ratio Mantel Haenszel Random [95%CI]; 0.75 [0.48, 1.16]; At 3 months of follow-up, the percentage of patients with a healed ulcer in each study was 22% and 52% with removable cast walkers, and 44% and 56% with therapeutic shoes.; GRADE evidence profile for cast walkers versus therapeutic shoes; Very low for percentage patients with a healed ulcer; Very low for time to healing
Elraiyah (2016)^37^; Inception – October 2011; (Medline, Embase, Cochrane, and Scopus); LOW | Patients with diabetic foot ulcers | Quantitative; RCT and observational; 19 studies | I: Off loading methods; C: any other offloading method | Rate of complete wound healing, time to complete wound healing, amputation | Although based on low-quality evidence (ie, evidence warranting lower certainty), benefits are demonstrated for use of total contact casting and irremovable cast walkers in the treatment of diabetic foot ulcers. Reduced relapse rate is demonstrated with various therapeutic shoes and insoles in comparison with regular footwear.; Therapeutic shoes and insoles versus regular footwear, relapse. Risk ratio = .34 [0.15, 0.79] p = 0.012
Bus (2015)^12^; May 1, 2006 – July 29, 2014 (PubMed, EMBASE, CINAHL, Cochrane, Database of Abstracts of Review of Effect, Central Register of Controlled Trials, National Health Service Economic Evaluation Database, Health Technology Assessment Database); LOW | Patients with diabetes mellitus type 1 or 2, and clinical problem addressed was a foot ulcer. | Qualitative; RCT and observational; 2 systematic reviews, 20 RCTs, 4 other controlled studies, 54 non-controlled studies | I:; 1. Casting; 2. Footwear; 3. Surgical offloading; 4. Other offloading techniques; C: any offloading technique or standard or care | Ulcer prevention and the reduction of mechanical pressure | The evidence base to support the use of interventions that prevent a first foot ulcer and prevent or heal nonplantar foot ulcers or ischemic or infected ulcers is practically non-existent.
Healy (2014)^36^; Inception – January 13, 2014; (CINAHL, Medline, and Cochrane); LOW | Participants had diabetes (type 1 or 2) and a current foot ulcer | Qualitative; RCT and observational; 17 studies | I: Footwear or a removable offloading device; C: another treatment, irremovable device, or repeated measure of a minimum 2 types of footwear or removable offloading device | Clinical assessment (ulcer healing rates/times or ulcer size) | From research to date in this area it is not possible to make strong conclusions on which footwear or removable offloading device is most effective for ulcer treatment; this is due to the lack of RCT studies conducted in this area. While further structured research with appropriately designed RCTs is needed, it appears that with regards to the use of footwear alone in the treatment of diabetic neuropathic ulcerations, currently available therapeutic shoes are the least effective intervention. This was followed by half or heel relief shoes with removable cast walkers found to be the most effective of the removable offloading devices.
Snyder (2014)^40^; NR; (PubMed); HIGH | Patients with diabetes | Qualitative; RCT and observational; consensus statement 2: 26 (4 SRs, 8 RCTs, 14 observational) | I: Offloading device or technique; C: other offloading device or technique | DFU healing | Consensus statement 2: Adequate offloading increases the likelihood of DFU healing (moderate/strong); Evidence is clear that adequate offloading increases the likelihood of DFU healing and that increased clinician use of effective offloading is necessary.; Consensus statement 6: The likelihood of DFU healing is increased with offloading adherence (moderate/strong).; The likelihood of DFU healing is increased with offloading adherence, and current evidence favors the use of nonremovable casts or fixed ankle walking braces as optimum offloading modalities.
Hunt (2011)^13^; Inception to September 2010 (Medline, Embase, Cochrane Library); HIGH | Adults with diabetes, with and without an ulcer | Qualitative; RCT and observational; 50 SRs and RCTs (2 studies (1 RCT and 1 observational related to KQ2)) | I: Interventions to prevent or treat foot ulcers and amputations; C: any | Ulcer healing rate | Felted foam padding applied to the skin compared with being inserted into footwear - felted foam padding applied to the skin and padding inserted into footwear seem equally effective at promoting ulcer healing.
Bus (2008)^14^; Inception to May 2006 (Medline, Embase, CINAHL, Cochrane, DARE, EED, and HTA); LOW | Adults with type 1 or 2 diabetes, with or without a foot ulcer | Qualitative; RCT and observational; 21 controlled, 108 uncontrolled/cross-sectional | I:; 1. Casting techniques; 2. Footwear-related techniques; 3. Surgical offloading techniques; 4. Other offloading techniques; C: any | Ulcer healing | There is a fairly strong evidence base showing that total contact casts heal a higher proportion of neuropathic plantar ulcers at a faster rate than other, mainly removable, offloading modalities. On the basis of the available evidence, therapeutic footwear does not appear suitable for ulcer treatment since other offloading modalities such as total contact casts are more effective.
Steed (2006)^15^; NR; (Previous guidelines, PubMed, Medline, Embase, Cochrane); HIGH | Patients with diabetes | Qualitative; RCT and observational; guideline 2.2 – 8 studies | I: Diagnosis, offloading, infection control, wound bed preparation, dressings, surgery, adjuvant agents (topical, device, systemic), and prevention recurrence; C: any | Healing, reulceration | Guideline 2.2: Acceptable methods of offloading include crutches, walkers, wheelchairs, custom shoes, depth shoes, shoe modifications, custom inserts, custom relief orthotic walkers (CROW), diabetic boots, forefoot and heel relief shoes, and total contact casts. (LEVEL I*); Principle: relieving pressure on the diabetic wound is necessary to maximize healing potential.; *Level I: Meta-analysis of multiple RCTs or at least two RCTs supporting the intervention of the guideline.

DFU: diabetic foot ulcer; RCT: randomized controlled trial; TCC: total contact cast; RCW: removable cast walker

Supplemental Table 7 KQ3 Citation Matrix

Included Studies* | Lazzarini^51^ | Healy^22^
Armstrong DG, van Schie CHM, Nguyen HC, Boulton AJM, Lavery LA, Harkless LB. Off-loading the diabetic foot wound – a randomized clinical trial. Diabetes Care. 2001; 24(6):1019–1022 11375363 11375363 | X | X
Armstrong DG, Lavery LA, Wu S, Boulton AJM. Evaluation of removable and irremovable cast walkers in the healing of diabetic foot wounds – a randomized controlled trial. Diabetes Care. 2005;28(3):551–554 15735186 | X | X
Armstrong DG, Lavery LA, Wrobel JS, Vileikyte L. Quality of life in healing diabetic wounds: does the end justify the means? Journal of Foot & Ankle Surgery. 2008;47(4):278–82 | | X
Burns J, Wegener C, Begg L, Vicaretti M, Fletcher J. Randomized trial of custom orthoses and footwear on foot pain and plantar pressure in diabetic peripheral arterial disease. Diabetic Medicine. 2009; 26(9):893–9 19719710 | | X
Bus SA, Waaijman R, Arts M, de Haart M, Busch-Westbroek T, van Baal J, . Effect of custom-made footwear on foot ulcer recurrence in diabetes: a multicenter randomized controlled trial. Diabetes Care. 2013; 36(12):4109–16.24130357 | | X
Bus SA, JJv N, Kottink AIR, . The efficacy of removable devices to offload and heal neuropathic plantar forefoot ulcers in people with diabetes: a single-blinded multicentre randomized controlled trial. Int Wound J. 2018; 15(1): 65–74 29057609 | X
Caravaggi C, Faglia E, DeGiglio R, . Effectiveness and safety of a non-removable fiberglass off-bearing cast versus a therapeutic shoe in the treatment of neuropathic foot ulcers: a randomized study. Diabetes Care. 2000;23(12):1746–1751 11128345 | X | X
Caravaggi C, Sgnazaroli A, Fabbi M, . Nonwindowed non-removable fiberglass off-loading cast versus removable pneumatic cast (AircastXP diabetic walker) in the treatment of neuropathic noninfected plantar ulcers. Diabetes Care. 2007;30(10):2577–2578 17563333 | X
Chakraborty PP, Ray S, Biswas D, . A comparative study between total contact cast and pressure-relieving ankle foot orthosis in diabetic neuropathic foot ulcers. J Diabetes Sci Technol. 2015; 9(2):302–308.25452635 | X
Dallimore SM, Kaminski MR. Tendon lengthening and fascia release for healing and preventing diabetic foot ulcers: a systematic review and meta-analysis. J Foot Ankle Res. 2015;8:33.26300980 | X
Elraiyah T, Prutsky G, Domecq JP, . A systematic review and meta-analysis of off-loading methods for diabetic foot ulcers. J Vasc Surg. 2016;63(2):59S–68S e1-2.26804369 | X
Faglia E, Caravaggi C, Clerici G, . Effectiveness of removable cast versus non-removable fiberglass off-bearing cast in the healing of diabetic plantar foot ulcer a randomized controlled trial. Diabetes Care. 2010; 33(7):1419–1423 20357377 | X | X
Ganguly S, Chakraborty K, Mandal PK, . A comparative study between total contact casting and conventional dressings in the non-surgical management of diabetic plantar foot ulcers. J Indian Med Assoc 2008; 106(4):237–239, 244.18828342 | X
Gutekunst DJ, Hastings MK, Bohnert KL, Strube MJ, Sinacore DR. Removable cast walker boots yield greater forefoot off-loading than total contact casts. Clin Biomech (Bristol, Avon). 2011;26(6):649–654 21496977 | X
Health Quality Ontario. Fibreglass total contact casting, removable cast walkers, and irremovable cast walkers to treat diabetic neuropathic foot ulcers: a health technology assessment. Ont Health Technol Assess Ser. 2017; 17(12):1–124 | x
Jeffcoate W, Game F, Turtle-Savage V, . Evaluation of the effectiveness and cost-effectiveness of lightweight fiberglass heel casts in the management of ulcers of the heel in diabetes: a randomize controlled trial. Health Technol Assess. 2017; 21(34): 1–92 | X
Johnson DJ, Saar BJ, Shevitz AJ, . A Total offloading foot brace for the treatment of diabetic foot ulcers: results from a halted randomized controlled trial. Wounds 2018;30(7):182–185 29718811 | X
Katz IA, Harlan A, Miranda-Palma B, . A randomized trial of two irremovable off-loading devices in the management of plantar neuropathic diabetic foot ulcers. Diabetes Care. 2005;28(3):555–559 15735187 | X
Lavery LA, Higgins KR, La Fontaine J, Zamorano RG, Constantinides GP, Kim PJ. Randomised clinical trial to compare total contact casts, healing sandals and a shear-reducing removable boot to heal diabetic foot ulcers. Int Wound J. 2015; 12(6):710–715 24618113 | X
Lewis J, Lipp A. Pressure-relieving interventions for treating diabetic foot ulcers. Cochrane Database Syst Rev. 2013;1:CD002302 | X
Martins de Oliveira AL, Moore Z. Treatment of the diabetic foot by offloading: a systematic review. J Wound Care 2015; 24(12):560, 562–570 26654736 | X
Miyan Z, Ahmed J, Zaidi Sl, Ahmedani MY, Fawwad A, Basit A. Use of locally made off-loading techniques for diabetic plantar foot ulcer in Karachi, Pakistan. Int Wound J. 2014; 11(6):691–695 23369009 | X | X
Morona JK, Buckley ES, Jones S, Reddin EA, Merlin TL. Comparison of the clinical effectiveness of different off-loading devices for the treatment of neuropathic foot ulcers in patients with diabetes: a systematic review and meta-analysis. Diabetes Metab Res Rev. 2013; 39(3):183–193. | X
Mueller MJ, Diamond JE, Sinacore DR, . Total contact casting in treatment of diabetic plantar ulcers. Controlled clinical trial. Diabetes Care. 1989; 12(6):384–388.2659299 | X
Najafi B, Grewal GS, Bharara M, Menzies R, Talal TK, Armstrong DG. Can’t stand the pressure: the association between unprotected standing, walking, and wound healing in people with diabetes. J Diabetes Sci Technol. 2017; 11(4):657–667.27510440 | X
Nube VL, Molyneaux L, Bolton T, Clingan T, Palmer E, Yue DK. The use of felt deflective padding in the management of plantar hallux and forefoot ulcers in patients with diabetes. The foot. 2006;16(1):38–43 | X
Paton JS, Stenhouse EA, Bruce G, Zahra D, Jones RB. A comparison of customized and prefabricated insoles to reduce risk factors for neuropathic diabetic foot ulceration: a participant-blinded randomized controlled trial. J. 2012;5(1):31 | | X
Piaggesi A, Macchiarini S, Rizzo L, . An off-the-shelf instant contact casting device for the management of diabetic foot ulcers – a randomized prospective trial versus traditional fiberglass cast. Diabetes Care. 2007;30(3):586–590 17327325 | X
Piaggesi A, Goretti C, Iacopi E, . Comparison of removable and irremovable walking boot to total contact casting in offloading the neuropathic diabetic foot ulceration. Foot Ankle Int 2016;37(8):855–861 27083507 | X
Reiber GE, Smith DG, Wallace C, Sullivan K, Hayes S, Vath C, . Effect of therapeutic footwear on foot reulceration in patients with diabetes: a randomized controlled trial. JAMA: Journal of the American Medical Association. 2002;287(19):2552.12020336 | | X
Rizzo L, Tedeshchi A, Fallani E, Coppelli A, Vallini V, lacopi E, . Custom-made orthesis and shoes in a structured follow-up program reduces the incidence of neuropathic ulcers in high-risk diabetic foot patients. Int. 2012; 11(1)59–64. | | X
Scire V, Leporati E, Teobaldi I, Nobili LA, Rizzo L, Piaggesi A. Effectiveness and safety of using podikon digital silicone padding in the primary prevention of neuropathic lesions in the forefoot of diabetic patients. Journal of the American Podiatric Medical Association. 2009; 99(1):28–34.19141719 | | X
Uccioli L, Faglia E, Monticone G, Favales F, Durola L, Aldeghi A, . Manufactured shoes in the prevention of diabetic foot ulcers. Diabetes Care. 1995; 18(10):1376–8.8721941 | | X
Ulbrecht JS, Hurley T, Mauger DT, Cavanagh PR. Prevention of recurrent foot ulcers with plantar pressure-based in-shoe orthoses: the CareFUL prevention multicenter randomized controlled trial. Diabetes Care. 2014; 37(7):1982–9.24760263 | | X
Van de Weg FB, Van Der Windt DA, Vahl AC. Wound healing: total contact cast vs. custom-made temporary footwear for patients with diabetic foot ulceration. Prosthet Orthot Int. 2008;32(1):3–11.17943623 | X | X
Zimny S, Schatz H, Pfohl U. The effects of applied felted foam on wound healing and healing times in the therapy of neuropathic diabetic foot ulcers. Diabet Med. 2003;20(8):622–625.12873288 | X