# APPENDIX D PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 4 | Yes | Thank you.
3 | 5 | Yes | Thank you.
4 | 6 | Yes | Thank you.
5 | 7 | Yes | Thank you.
6 | 8 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
7 | 1 | No | Thank you.
8 | 4 | No | Thank you.
9 | 5 | No | Thank you.
10 | 6 | No | Thank you.
11 | 7 | No | Thank you.
12 | 8 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
13 | 1 | No | Thank you.
14 | 4 | No | Thank you.
15 | 5 | No | Thank you.
16 | 6 | No | Thank you.
17 | 7 | No | Thank you.
18 | 8 | No | Thank you.
Additional suggestions or comments can be provided below.
19 | 1 | In discussion of PODUS 2020 clinical applicability (pg.45, Line 55-60) I would have liked to have seen some mention of provider inconsistency in reliable use of monofilament, monofilament calibration, and provider interpretation. However, the evidence review, methodology, and description were well done. | Thank you. We have added the below statement to Discussion Sections in Executive Summary (page 15) and Full Report (page 46):; “The prognostic performance of PODUS 2020 depends on the ability of clinicians to accurately assess for neuropathy using a 10 g monofilament, and palpable pedal pulses. Although our evidence review did not formally conduct a primary literature review of the performance characteristics of these clinically assessed variables included in PODUS 2020, one study showed sub-optimal validity and reliability (inter- and intra-rater).^44^ Performance characteristics for these variables (neuropathy and arterial disease) likely also varies based on clinicians’ specialty and experience. Future research could systematically examine the literature for studies describing the performance characteristics of these clinically assessed variables or conduct such studies if not done.”; Also, entered an abbreviated version on this in Future research page 49
20 | 4 | Non-content related issues observed:; 1 P23 Table 1 – error; reference not found comment | Thank you, we have updated the formatting and the issue was resolved.
21 | 4 | 2 In a few instances, the acronyms DFU were interchanged with DUF. Perhaps these were references to a source article who used the acronym this way?? | Thank you, this was an error. We have corrected this to use the acronym DFU throughout.
22 | 4 | 3 The organization and layout of the document flows nicely. | Thank you.
23 | 4 | Content related observations:; The authors distill the content into conclusions. Further, in the discussion, authors layout ‘key findings’ which helps readers grab the takeaway points. A few suggestions on this:; Consider re-naming the ‘key findings’ into ‘evidence (or empirical) evidence statements. In doing so, it seems one speaks in first person (‘we did not’). Consider not having any first person language in this section. Then also consider referencing the evidence that supports each key finding. Then finally, based on the strength of the evidence supporting each key finding (empirical evidence statement), consider adding either a strength of evidentiary support or a confidence in the evidence (ie low, moderate, high) just to add a bit more emphasis and objectivity so that the policy office or researchers who may pick this up, have a sense of how strong the statement is and what may be acted upon as stated compared with what may need further study before implementing. | Thank you for the thoughtful and supportive observations. The current framework for evaluating the certainty of evidence that is commonly used is GRADE. For this report, the certainty (or strength) of evidence was not assessed because there are not well-established methods for using GRADE in “umbrella reviews” (review of reviews). Furthermore, most of the individual reviews that informed our key questions did not formally use GRADE or other methods to assess certainty of findings and provided only a narrative or qualitative summary of findings. For the reviews that did assess certainty of evidence we captured those findings in the review characteristics table. We did perform and reported on the Risk of Bias using the ROBIS tool to assess the quality of the systematic reviews which provides some information about the confidence in the results of specific reviews. Therefore, as GRADE was not performed, we believe the term “Key Findings” ais more appropriate and is also more consistent with most VA-ESP report formats. We removed the first person language in the key findings.
24 | 5 | The review of reviews is very good. I really don’t have any significant comments regarding the content of the review. The only comment that I have is in the Executive Summary section in the paragraph below.; “Although PODUS 2020 predicts risk of DFU at 2 years, no data exist to inform how risks change over time and appropriate re-screening intervals for any tool. Thus, it is uncertain how often patients with DM should be screened for risk of DFU or amputation. Frequent screening intervals of 1 year are unlikely to yield better risk stratification.”; Comment – may want to clarify the last sentence; “Frequent screening intervals of 1 year are unlikely to yield better risk stratification.” | We have deleted this sentence from the executive summary. We do however, comment further in the Discussion Sections in Executive Summary (page 15) and Full Report (page 47):; Lastly, all studies of the identified tools, including PODUS 2020, assessed one-time use of the tool to predict DFU development or amputation at subsequent time horizons ranging from 1 to 5 years (2 years for PODUS 2020). There were no studies of sequential use of the tools at defined time intervals to identify how risks for DFU development change over time. Although VA guidelines recommend rescreening annually for DFU risk using PAVE, the benefit of re-screening or the appropriate re-screening interval (if done) for DFU risk with any tool is unknown.; Also, entered an abbreviated version on this in Future research page 49
25 | 6 | The results are not surprising considering the variability of the inclusion and exclusion criteria of the studies reviewed as well as the quality of protoplasm individual patients present. I think the conclusions are accurate and indicate that the tool works, in most circumstances, that proper footwear works in many circumstances and that off-loading devices, especially TCC are effective in many circumstances. | Thank you. As stated in the key findings and discussion we caution that the evidence is limited regarding the effectiveness and comparative effectiveness of offloading and therapeutic footwear prevents the development of primary and recurrent DFU. There is some evidence that total contact casts and other devices may improve DFU healing, however the issue of adherence with these other devices confounds the association between the devices and treatment of DFU and must be considered. Future research should consider investigating and addressing patient adherence of these devices in the prevention and treatment of DFU. We modified this paragraph to highlight these points
26 | 7 | Outstanding report with clear and concise conclusions. My only concern is the definition of offloading. I recognize that it is inconsistent in the literature and not a reflection of the reviewers language selection. However, in bullet 5 of the key findings and in response to KQ2 “offloading” appears to be reporting on accommodative insoles being used with therapeutic footwear. This may lead to confusion by readers. Total contact casts, removable devices that cross the ankle are offloading by design, but the accommodative insoles that are described with therapeutic footwear are not offloading. Therefore, in bullet 6 of the key findings, saying “While methodological limitations exist in the primary literature and systematic reviews of offloading footwear, total contact casts (TCC) and available removable devices may improve DFU healing,” may also lead to confusion because a TCC is by definition offloading footwear. If it is appropriate, may benefit the report to modify the term offloading to accommodative insoles when referring to prescribed inserts that are placed within therapeutic footwear with the goal to prevent development of primary and recurrent DFU. | Thank you for this clarification, we have updated.
27 | 8 | In multiple places the report says “predict risks” or “risk prediction tools.” That language is unclear to me. A prediction is a probability and risk can be a probability too. It would be similar to saying “we are going to predict what the weather forecast will be” when the aim is to predict what the actual weather will be. You could just say “predict DFUs” or “predict ulcers.” I assume the writers are thinking of risk as an absolute risk or relative risk which is an event but makes the meaning less clear since the meaning of risk in that research-based situation is different from the meaning in everyday language. There are at least a couple of “its’”. The possessive form of “it” is just “its”; no apostrophe. Unless a usage manual for research says differently. On page ii, line 5 it says “Minneapolis VA Portland Health Care System.” Sounds like “Portland” got added accidentally or an “and” got left out. | Thank you. We agree, we have clarified throughout the manuscript that the tools predict DFU development or amputation. The Minneapolis VA error has also been corrected.