# APPENDIX C QUALITY ASSESSMENT

## CRITERIA USED IN ASSESSING RISK OF BIAS (ROBIS TOOL)

## RISK OF BIAS RATINGS FOR ALL ELIGIBLE SYSTEMATIC REVIEWS

Author, Year | Domain 1 Summary: Concerns regarding specification of study eligibility criteria | Domain 2 Summary: Concerns regarding methods used to identify and/or select studies | Domain 3 Summary: Concerns regarding methods used to collect data and appraise studies | Domain 4 Summary: Concerns regarding the synthesis and findings | Overall risk of bias in the review
Arad, 2011^30^ | Low | Unclear | Unclear | Low | Moderate
Beulens, 2021^16^ | Low | Low | Low | Low | Low
Bus, 2016^12^ | Low | Low | Low | Unclear | Low
Bus, 2008^14^ | Low | Low | Low | Low | Low
Crawford, 2020^23^ | Low | Low | Low | Low | Low
Elraiyah, 2016^37^ | Low | Low | Low | Low | Low
Fernandez-Torres, 2020^19^ | Low | Unclear | Unclear | Unclear | Moderate
Healy, 2018^38^ | Low | Low | Low | Low | Low
Healy, 2014^36^ | Low | Low | Low | Low | Low
Healy, 2013^25^ | Low | Low | Low | Low | Low
Heuch, 2016^29^ | Low | Unclear | Unclear | Low | Moderate
Hingorani, 2016^31^ | High | High | High | High | High
Hunt, 2011^13^ | Low | Unclear | High | Unclear | High
Health Quality Ontario, 2017^39^ | Low | Unclear | High | Low | Moderate
Jarl, 2016^32^ | High | High | High | Unclear | High
Karthikesalingam, 2010^21^ | Low | Unclear | High | Low | High
Lazzarini, 2020^35^ | Low | Low | Low | Low | Low
Singh, 2005^33^ | Low | Unclear | High | Low | High
Mason, 1999^34^ | Low | Low | High | High | High
Alahakoon, 2020^28^ | Low | Unclear | Unclear | Low | Moderate
Monteiro-Soares, 2021^18^ | Low | Low | Low | Unclear | Moderate
Monteiro-Soares, 2014^20^ | Low | Low | Unclear | Low | Moderate
Monteiro-Soares, 2011^17^ | Low | Low | Low | Low | Low
Crawford, 2020^11^ | Low | Low | Low | Low | Low
O’Meara, 2000^27^ | Low | Low | Low | Low | Low
Paton, 2011^26^ | Low | Low | Low | Low | Low
Snyder, 2014^40^ | High | High | High | High | High
Steed, 2006^15^ | High | Unclear | High | High | High
van Netten, 2020^22^ | Low | Low | Low | Low | Low
van Netten, 2016^24^ | Low | Low | Low | Low | Low