# APPENDIX B EXCLUDED STUDIES

1 Adler AI, Erqou S, Lima TAS, Robinson AHN. Association between glycated haemoglobin and the risk of lower extremity amputation in patients with diabetes mellitus-review and meta-analysis. Diabetologia. 2010;53(5):840–849. Ineligible intervention.20127309
2 Andrews KL, Houdek MT, Kiemele LJ. Wound management of chronic diabetic foot ulcers: from the basics to regenerative medicine. Prosthetics and orthotics international. 2015;39(1):29–39. Ineligible intervention.25614499
3 Bakker K, Apelqvist J, Lipsky BA, Van Netten JJ, International Working Group on the Diabetic F. The 2015 IWGDF guidance documents on prevention and management of foot problems in diabetes: development of an evidence-based global consensus. Diabetes/metabolism research and reviews. 2016;32 Suppl 1:2–6. Ineligible study design.
4 Barrera MdP, Sanchez AL, Mejia A, Pinilla AE. Risk factors of diabetes mellitus and diabetic foot: A primary approach to prevention. Revista Colombiana de Cardiologia. 2013;20(4):213–222. Ineligible intervention.
5 Bergin SM, Gurr JM, Allard BP, . Australian Diabetes Foot Network: management of diabetes-related foot ulceration - a clinical update. The Medical journal of Australia. 2012;197(4):226–229. Ineligible study design.22900873
6 Blanchette V, Brousseau-Foley M, Cloutier L. Evaluation and perspectives of podiatric interventions performed in multidisciplinary context on lower extremity amputations. Journal of Diabetes Science and Technology. 2020;14(3):676. Ineligible study design.
7 Borkosky SL, Roukis TS. Incidence of re-amputation following partial first ray amputation associated with diabetes mellitus and peripheral sensory neuropathy: A systematic review. Diabetic Foot and Ankle. 2012;3. Ineligible intervention.
8 Bradley CP, Buckley CM, Perry IJ, Kearney PM. Does contact with a podiatrist prevent the occurrence of a lower extremity amputation in people with diabetes? A systematic review and meta-analysis. BMJ Open. 2013;3(5):6. Ineligible intervention.
9 Brownrigg JRW, Hinchliffe RJ, Apelqvist J, . Performance of prognostic markers in the prediction of wound healing or amputation among patients with foot ulcers in diabetes: a systematic review. Diabetes/metabolism research and reviews. 2016;32 Suppl 1:128–135. Ineligible intervention.26342129
10 Bus SA, Van Netten JJ, Hinchliffe RJ, . Standards for the development and methodology of the 2019 International Working Group on the Diabetic Foot guidelines. Diabetes/metabolism research and reviews. 2020;36 Suppl 1:e3267. Ineligible study design.31916377
11 Bus SA, van Netten JJ, Monteiro-Soares M, Lipsky BA, Schaper NC. Diabetic foot disease: “The Times They are A Changin’ ”. Diabetes/metabolism research and reviews. 2020;36 Suppl 1:e3249. Ineligible study design.32176443
12 Chan KS, Lo ZJ. Wound assessment, imaging and monitoring systems in diabetic foot ulcers: A systematic review. International Wound Journal. 2020;17(6):1909–1923. Ineligible intervention.32830440
13 Chappell FM, Crawford F, Horne M, . Development and validation of a clinical prediction rule for development of diabetic foot ulceration: an analysis of data from five cohort studies. BMJ open diabetes research & care. 2021;9(1). Ineligible intervention.
14 Chen PY, Elmer S, Callisaya M, Wills K, Greenaway TM, Winzenberg TM. Associations of health literacy with diabetic foot outcomes: a systematic review and meta-analysis. Diabetic medicine : a journal of the British Diabetic Association. 2018;35(11):1470–1479. Ineligible intervention.29802639
15 Collings R, Glasser S, Freeman J, Latour JM, Paton J. Footwear and insole design features to prevent foot ulceration in people with diabetes: A systematic review protocol. JBI Database of Systematic Reviews and Implementation Reports. 2017;15(7):1824–1834. Ineligible study design.28708747
16 Crawford F, Anandan C, Chappell FM, . Protocol for a systematic review and individual patient data meta-analysis of prognostic factors of foot ulceration in people with diabetes: the international research collaboration for the prediction of diabetic foot ulcerations (PODUS). BMC medical research methodology. 2013;13:22. Ineligible study design.23414550
17 Crawford F, Cezard G, Chappell FM, Group P. The development and validation of a multivariable prognostic model to predict foot ulceration in diabetes using a systematic review and individual patient data meta-analyses. Diabetic medicine : a journal of the British Diabetic Association. 2018;35(11):1480–1493. Ineligible intervention.30102422
18 Crawford F, Cezard G, Chappell FM, . A systematic review and individual patient data meta-analysis of prognostic factors for foot ulceration in people with diabetes: the international research collaboration for the prediction of diabetic foot ulcerations (PODUS). Health technology assessment (Winchester, England). 2015;19(57):1–210. Ineligible intervention.
19 Dillon MP, Quigley M, Fatone S. A systematic review describing incidence rate and prevalence of dysvascular partial foot amputation; how both have changed over time and compare to transtibial amputation. Systematic reviews. 2017;6(1):230. Ineligible intervention.29162147
20 Dinh TL, Veves A. A review of the mechanisms implicated in the pathogenesis of the diabetic foot. International Journal of Lower Extremity Wounds. 2005;4(3):154–159. Ineligible study design.16100096
21 Dorresteijn JAN, Kriegsman DMW, Assendelft WJJ, Valk GD. Patient education for preventing diabetic foot ulceration. The Cochrane database of systematic reviews. 2014(12):CD001488. Ineligible intervention.25514250
22 Dorresteijn JAN, Kriegsman DMW, Valk GD. Complex interventions for preventing diabetic foot ulceration. The Cochrane database of systematic reviews. 2010(1):CD007610. Ineligible intervention.20091642
23 Droste S, Schuster B, Narres M, . Incidence of lower extremity amputations in the diabetic compared with the non-diabetic population: A systematic review. PLoS ONE. 2017;12(8):e0182081. Ineligible intervention.28846690
24 Dumville JC, Deshpande S, O’Meara S, Speak K. Foam dressings for healing diabetic foot ulcers. The Cochrane database of systematic reviews. 2011(9):CD009111. Ineligible intervention.21901731
25 Ena J, Carretero-Gomez J, Arevalo-Lorido JC, Sanchez-Ardila C, Zapatero-Gaviria A, Gomez-Huelgas R. The Association Between Elevated Foot Skin Temperature and the Incidence of Diabetic Foot Ulcers: A Meta-Analysis. International Journal of Lower Extremity Wounds. 2021;20(2):111–118. Ineligible intervention.32106729
26 Feng Y, Schlosser FJ, Sumpio BE. The Semmes Weinstein monofilament examination is a significant predictor of the risk of foot ulceration and amputation in patients with diabetes mellitus. Journal of vascular surgery. 2011;53(1):220–225. Ineligible intervention.20692793
27 Fernandez-Torres R, Ruiz-Munoz M, Perez-Panero AJ, Garcia-Romero J, Gonzalez-Sanchez M. Instruments of choice for assessment and monitoring diabetic foot: A systematic review. Journal of Clinical Medicine. 2020;9(2):602. Ineligible intervention.32102313
28 Firdaus MKZH, Jittanoon P. A literature review on intervention programs for diabetic foot care. Enfermeria clinica. 2021;31 Suppl 2:S243–S246. Ineligible intervention.
29 Formosa C, Gatt A, Chockalingam N. A Critical Evaluation of Existing Diabetic Foot Screening Guidelines. The review of diabetic studies : RDS. 2016;13(2–3):158–186. Ineligible intervention.28012281
30 Forsythe RO, Apelqvist J, Boyko EJ, . Performance of prognostic markers in the prediction of wound healing or amputation among patients with foot ulcers in diabetes: A systematic review. Diabetes/metabolism research and reviews. 2020;36 Suppl 1:e3278. Ineligible intervention.32176442
31 Freeman J, Paton J, Collings R, Latour JM. Footwear and insole design features for offloading the diabetic at risk foot-A systematic review and meta-analyses. Endocrinology, Diabetes and Metabolism. 2021;4(1):e00132. Ineligible intervention.
32 Grimmer K, Smith C, Kumar S, Jones S. The clinical effectiveness of podiatric management in the treatment of Charcot foot. JBI Library of Systematic Reviews. 2014;3(7 SUPPL.):S59–S73. Ineligible population.
33 Hoogeveen RC, Dorresteijn JAN, Kriegsman DMW, Valk GD. Complex interventions for preventing diabetic foot ulceration. The Cochrane database of systematic reviews. 2015(8):CD007610. Ineligible intervention.26299991
34 Huang Z-H, Li S-Q, Kou Y, Huang L, Yu T, Hu A. Risk factors for the recurrence of diabetic foot ulcers among diabetic patients: a meta-analysis. International wound journal. 2019;16(6):1373–1382. Ineligible intervention.31489774
35 Jalilian M, Sarbarzeh PA, Oubari S. Factors related to severity of diabetic foot ulcer: A systematic review. Diabetes, Metabolic Syndrome and Obesity: Targets and Therapy. 2020;13:1835–1842. Ineligible intervention.32547145
36 Jenkins DA, Mohamed S, Taylor JK, Peek N, van der Veer SN. Potential prognostic factors for delayed healing of common, non-traumatic skin ulcers: A scoping review. International wound journal. 2019;16(3):800–812. Ineligible intervention.30821117
37 Jones P, Bibb R, Davies M, . Prediction of Diabetic Foot Ulceration: The Value of Using Microclimate Sensor Arrays. Journal of diabetes science and technology. 2020;14(1):55–64. Ineligible intervention.31596145
38 Jones P, Bus SA, Khunti K, Webb D, Davies MJ. Toe gaps and their assessment in footwear for people with diabetes: a narrative review. Journal of foot and ankle research. 2020;13(1):70. Ineligible intervention.33276804
39 Jones P, Khunti K, Webb D, Davies MJ, Fong DTP. In-shoe pressure thresholds for people with diabetes and neuropathy at risk of ulceration: A systematic review. Journal of Diabetes and its Complications. 2021;35(3):107815. No eligible outcomes.33280984
40 Kassianos G, Bracknell GP. A summary of the National Institute for Health and Clinical Excellence (NICE) Clinical Guideline 66: The management of type 2 diabetes. Drugs in Context. 2008;4(2):185–190. Ineligible study design.
41 Kaufman MW, Bowsher JE. Preventing diabetic foot ulcers. Medsurg nursing : official journal of the Academy of Medical-Surgical Nurses. 1994;3(3):204–210. Ineligible study design.8055038
42 Korada H, Maiya A, Rao SK, Hande M. Effectiveness of customized insoles on maximum plantar pressure in diabetic foot syndrome: A systematic review. Diabetes & metabolic syndrome. 2020;14(5):1093–1099. No eligible outcomes.32652497
43 Lauri C, Tamminga M, Glaudemans AWJM, . Detection of Osteomyelitis in the Diabetic Foot by Imaging Techniques: A Systematic Review and Meta-analysis Comparing MRI, White Blood Cell Scintigraphy, and FDG-PET. Diabetes care. 2017;40(8):1111–1120. Ineligible intervention.28733376
44 Li D, Yang JY, Wang T, Shen S, Tang H. Risks of diabetic foot syndrome and amputation associated with sodium glucose co-transporter 2 inhibitors: A Meta-analysis of Randomized Controlled Trials. Diabetes & metabolism. 2018;44(5):410–414. Ineligible intervention.29506779
45 Lin C, Liu J, Sun H. Risk factors for lower extremity amputation in patients with diabetic foot ulcers: A meta-analysis. PloS one. 2020;15(9):e0239236. Ineligible intervention.32936828
46 Lipsky BA, Peters EJG, Berendt AR, . Specific guidelines for the treatment of diabetic foot infections 2011. Diabetes/metabolism research and reviews. 2012;28 Suppl 1:234–235. Ineligible study design.22271744
47 Margolis DJ, Kantor J, Santanna J, Strom BL, Berlin JA. Risk factors for delayed healing of neuropathic diabetic foot ulcers: a pooled analysis. Archives of dermatology. 2000;136(12):1531–1535. Ineligible intervention.11115166
48 Mason J, O’Keeffe C, Hutchinson A, McIntosh A, Young R, Booth A. A systematic review of foot ulcer in patients with Type 2 diabetes mellitus. II: treatment. Diabetic medicine : a journal of the British Diabetic Association. 1999;16(11):889–909. Ineligible intervention.10588519
49 Mayfield JA, Reiber GE, Sanders LJ, Janisse D, Pogach LM, American Diabetes A. Preventive foot care in people with diabetes. Diabetes care. 2003;26 Suppl 1:S78–79. Ineligible intervention.12502623
50 McGinnis E, Stubbs N. Pressure-relieving devices for treating heel pressure ulcers. The Cochrane database of systematic reviews. 2014(2):CD005485. Ineligible population.24519736
51 Meneses JCBCd, Viana MCA, Reboucas VdCF, Alencar AMPG, Borges JWP, Silva ARVd. The effects of felted foam in diabetic foot treatment: systematic review with meta-analysis. Revista da Escola de Enfermagem da U S P. 2020;54:e03640. Ineligible intervention.33331499
52 Meza-Torres B, Carinci F, Heiss C, Joy M, de Lusignan S. Health service organisation impact on lower extremity amputations in people with type 2 diabetes with foot ulcers: systematic review and meta-analysis. Acta diabetologica. 2021;58(6):735–747. Ineligible intervention.33547497
53 Minc SD, Fogg LF, McCarthy WJ, Shah RC. Racial disparities in primary amputation vs revascularization for critical limb ischemia: A meta-analysis. Journal of the American College of Surgeons. 2017;225(4 Supplement 2):e778. Ineligible intervention.
54 Mizzi A, Formosa C, Cassar K, Bowen C. A review of the temporal progression of intermittent claudication: Implications for the diabetic foot. Diabetic Medicine. 2018;35(Supplement 1):87. Ineligible study design.
55 Monteiro-Soares M, Boyko EJ, Ribeiro J, Ribeiro I, Dinis-Ribeiro M. Predictive factors for diabetic foot ulceration: a systematic review. Diabetes/metabolism research and reviews. 2012;28(7):574–600. Ineligible intervention.22730196
56 Morrison T, Jones S, Causby RS, Thoirs K. Can ultrasound measures of intrinsic foot muscles and plantar soft tissues predict future diabetes-related foot disease? A systematic review. PloS one. 2018;13(6):e0199055. Ineligible intervention.29906277
57 Mulder G, Tenenhaus M, D’Souza GF. Reduction of diabetic foot ulcer healing times through use of advanced treatment modalities. The international journal of lower extremity wounds. 2014;13(4):335–346. Ineligible intervention.25384916
58 Norman G, Cullum N, Westby M, Vedhara K, Game F. Psychosocial and behavioural prognostic factors for diabetic foot ulcer development and healing: a systematic review. Diabetic Medicine. 2020;37(8):1244–1255. Ineligible intervention.32315474
59 Novice T, Vemuri C, Gilbert C, Fici AJ, Vanwieren EF, Schmidt BM. Willingness to adopt devices for prevention of foot ulcers in high-risk diabetic patients. Diabetes. 2019;68(Supplement 1). Ineligible intervention.
60 Ousey K, Chadwick P, Jawien A, . Identifying and treating foot ulcers in patients with diabetes: saving feet, legs and lives. Journal of wound care. 2018;27(Sup5):S1–S52. Ineligible study design.
61 Paton J, Glasser S, Collings R, Kent B. The effects of foot and ankle devices on balance, gait and falls in adults with sensory perception loss: A systematic review protocol. JBI Database of Systematic Reviews and Implementation Reports. 2014;12(11):74–91. No eligible outcomes.
62 Patry J, Belley R, Cote M, Chateau-Degat M-L. Plantar pressures, plantar forces, and their influence on the pathogenesis of diabetic foot ulcers: a review. Journal of the American Podiatric Medical Association. 2013;103(4):322–332. No eligible outcomes.23878385
63 Perez-Panero AJ, Ruiz-Munoz M, Cuesta-Vargas AI, Gonzalez-Sanchez M. Prevention, assessment, diagnosis and management of diabetic foot based on clinical practice guidelines: A systematic review. Medicine. 2019;98(35):e16877. Ineligible intervention.31464916
64 Pinzur MS, Slovenkai MP, Trepman E. Guidelines for diabetic foot care. The Diabetes Committee of the American Orthopaedic Foot and Ankle Society. Foot & ankle international. 1999;20(11):695–702. Ineligible study design.10582844
65 Pinzur MS, Slovenkai MP, Trepman E, Shields NN, Diabetes Committee of American Orthopaedic F, Ankle S. Guidelines for diabetic foot care: recommendations endorsed by the Diabetes Committee of the American Orthopaedic Foot and Ankle Society. Foot & ankle international. 2005;26(1):113–119. Ineligible study design.15680122
66 Przestrzelski B, Walker K, Stanley S, . Novel additive-manufactured foot orthotic achieves comfort equivalent to the traditional standard. Journal of Orthopaedic Research. 2016;34(Supplement 1). Ineligible study design.
67 Ragnarson Tennvall G, Apelqvist J. Prevention of diabetes-related foot ulcers and amputations: a cost-utility analysis based on Markov model simulations. Diabetologia. 2001;44(11):2077–2087. No eligible outcomes.11719840
68 Raikou M, McGuire A. The economics of screening and treatment in type 2 diabetes mellitus. PharmacoEconomics. 2003;21(8):543–564. No eligible outcomes.12751913
69 Raji S, Tariq G. Implementing a lean methodology in diabetic foot care management. Journal of Wound Care. 2017;26(SUPPL 6):313–320. Ineligible study design.
70 Richard J-L, Lavigne J-P, Sotto A. Diabetes and foot infection: more than double trouble. Diabetes/metabolism research and reviews. 2012;28 Suppl 1:46–53. Ineligible study design.22271723
71 Rodriguez-Sanchez B, Pena-Longobardo LM, Sinclair AJ. Cost-effectiveness analysis of the Neuropad device as a screening tool for early diabetic peripheral neuropathy. European Journal of Health Economics. 2020;21(3):335–349. Ineligible intervention.
72 Saliba Thorne C, Gatt A, DeRaffaele C, Bazena A, Formosa C. Digital foot health technology and diabetic foot monitoring: A systematic review. Diabetes research and clinical practice. 2021;175:108783. Ineligible intervention.33775686
73 Schaper NC, van Netten JJ, Apelqvist J, . Practical Guidelines on the prevention and management of diabetic foot disease (IWGDF 2019 update). Diabetes/metabolism research and reviews. 2020;36 Suppl 1:e3266. Ineligible study design.32176447
74 Schaper NC, Van Netten JJ, Apelqvist J, Lipsky BA, Bakker K. Prevention and management of foot problems in diabetes: A Summary Guidance for Daily Practice 2015, based on the IWGDF guidance documents. Diabetes Research and Clinical Practice. 2017;124:84–92. Ineligible study design.28119194
75 Seixas A, Ammer K, Carvalho R, Vilas-Boas JP, Mendes J, Vardasca R. The use of thermal imaging in patients with diabetic foot: Protocol for a systematic review. Thermology International. 2018;28(3):133–138. Ineligible intervention.
76 Sen P, Demirdal T, Emir B. Meta-analysis of risk factors for amputation in diabetic foot infections. Diabetes/metabolism research and reviews. 2019;35(7):e3165. Ineligible intervention.30953392
77 Senneville E, Lipsky BA, Abbas ZG, . Diagnosis of infection in the foot in diabetes: a systematic review. Diabetes/metabolism research and reviews. 2020;36 Suppl 1:e3281. Ineligible intervention.32176440
78 Sharma S, Gupta R, Compay A, . Identification of diagnostic and prognostic biomarkers to improve the management of diabetes-related ulcers. Asian Pacific Journal of Tropical Disease. 2014;4(3):228. Ineligible study design.
79 Shin JY, Roh S-G, Lee N-H, Yang K-M. Influence of Epidemiologic and Patient Behavior-Related Predictors on Amputation Rates in Diabetic Patients: Systematic Review and Meta-Analysis. The international journal of lower extremity wounds. 2017;16(1):14–22. Ineligible intervention.28682679
80 Shin JY, Roh S-G, Sharaf B, Lee N-H. Risk of major limb amputation in diabetic foot ulcer and accompanying disease: A meta-analysis. Journal of plastic, reconstructive & aesthetic surgery : JPRAS. 2017;70(12):1681–1688. No eligible outcomes.28865989
81 Snyder RJ, Hanft JR. Diabetic foot ulcers - Effects on quality of life, costs, and mortality and the role of standard wound care and advanced-care therapies in healing: A review. Ostomy Wound Management. 2009;55(11):28–38. No eligible outcomes.19934461
82 Strayer ST, Moghaddam SRM, Beschorner KE, Gusenoff B, Gusenoff J. Contact pressures between the rearfoot and a novel offloading insole: Results from a finite element analysis study. Journal of Applied Biomechanics. 2020;36(5):326–333. Ineligible study design.
83 Tan LS. The clinical use of the 10g monofilament and its limitations: a review. Diabetes research and clinical practice. 2010;90(1):1–7. Ineligible intervention.20655123
84 Tang Z-Q, Chen H-L, Zhao F-F. Gender differences of lower extremity amputation risk in patients with diabetic foot: a meta-analysis. The international journal of lower extremity wounds. 2014;13(3):197–204. Ineligible intervention.25106444
85 Tay WL, Lo ZJ, Hong Q, Yong E, Chandrasekar S, Tan GWL. Toe Pressure in Predicting Diabetic Foot Ulcer Healing: A Systematic Review and Meta-analysis. Annals of vascular surgery. 2019;60:371–378. Ineligible intervention.31220591
86 Tolossa T, Mengist B, Mulisa D, Fetensa G, Turi E, Abajobir A. Prevalence and associated factors of foot ulcer among diabetic patients in Ethiopia: a systematic review and meta-analysis. BMC public health. 2020;20(1):41. Ineligible intervention.31924173
87 Tsapas A, Liakos A, Paschos P, . A simple plaster for screening for diabetic neuropathy: a diagnostic test accuracy systematic review and meta-analysis. Metabolism: clinical and experimental. 2014;63(4):584–592. Ineligible intervention.24405753
88 Tu HA, Costa V, Xie X, . Cost-effectiveness of fiberglass total contact casting, irremovable cast walkers and removable cast walkers in the treatment of patients with diabetic foot ulcers in Ontario, Canada. Value in Health. 2017;20(5):A242. Ineligible intervention.
89 van Netten JJ, Sacco ICN, Lavery LA, . Treatment of modifiable risk factors for foot ulceration in persons with diabetes: a systematic review. Diabetes/metabolism research and reviews. 2020;36 Suppl 1:e3271. Ineligible intervention.31957306
90 van Reijen NS, Ponchant K, Ubbink DT, Koelemay MJW. Editor’s Choice - The Prognostic Value of the WIfI Classification in Patients with Chronic Limb Threatening Ischaemia: A Systematic Review and Meta-Analysis. European journal of vascular and endovascular surgery : the official journal of the European Society for Vascular Surgery. 2019;58(3):362–371. Ineligible population.31230866
91 Wang L, Jones D, Alazmani A, . A Review of Wearable Sensor Systems to Monitor Plantar Loading in the Assessment of Diabetic Foot Ulcers. IEEE Transactions on Biomedical Engineering. 2020;67(7):1989–2004. Ineligible intervention.31899409
92 Wang N, Yang B-H, Wang G, . A meta-analysis of the relationship between foot local characteristics and major lower extremity amputation in diabetic foot patients. Journal of cellular biochemistry. 2019;120(6):9091–9096. Ineligible intervention.30784095
93 Wang Z, Hasan R, Firwana B, . A systematic review and meta-analysis of tests to predict wound healing in diabetic foot. Journal of vascular surgery. 2016;63(2 Suppl):29S–22. Ineligible intervention.26804365
94 Woods T-J, Tesfay F, Speck P, Kaambwa B. Economic evaluations considering costs and outcomes of diabetic foot ulcer infections: A systematic review. PloS one. 2020;15(4):e0232395. No eligible outcomes.32353082
95 Wraight PR, Lawrence SM, Campbell DA, Colman PG. Creation of a multidisciplinary, evidence based, clinical guideline for the assessment, investigation and management of acute diabetes related foot complications. Diabetic medicine : a journal of the British Diabetic Association. 2005;22(2):127–136. Ineligible intervention.15660728
96 Wu X-J, Fan L. Sex difference for the risk of amputation in diabetic patients: A systematic review and meta-analysis. PLoS ONE. 2021;16(3 March):e0243797. Ineligible intervention.33705430
97 Yammine K, Assi C. Surgery Versus Nonsurgical Methods in Treating Neuropathic Plantar Forefoot Ulcers: A Meta-Analysis of Comparative Studies. International Journal of Lower Extremity Wounds. 2020. Ineligible study design.
98 Zhang Y, Cramb S, van Netten JJ, . Diabetes-related foot disease in Australia: a systematic review of the prevalence and incidence of risk factors, disease and amputation in Australian populations. Journal of foot and ankle research. 2021;14(1):8. Ineligible intervention.33468226