# REFERENCES

1 Yong RJ, Mullins PM, Bhattacharyya N. Prevalence of chronic pain among adults in the United States. Pain. Feb 1 2022;163(2):e328–e332. doi:10.1097/j.pain.0000000000002291 33990113
2 Global, regional, and national burden of osteoarthritis, 1990-2020 and projections to 2050: a systematic analysis for the Global Burden of Disease Study 2021. Lancet Rheumatol. Sep 2023;5(9):e508–e522. doi:10.1016/s2665-9913(23)00163-7 37675071
3 McDonough CM, Jette AM. The contribution of osteoarthritis to functional limitations and disability. Clin Geriatr Med. Aug 2010;26(3):387–99. doi:10.1016/j.cger.2010.04.001 20699161
4 Yelin E, Weinstein S, King T. The burden of musculoskeletal diseases in the United States. Semin Arthritis Rheum. Dec 2016;46(3):259–260. doi:10.1016/j.semarthrit.2016.07.013 27519477
5 Song J, Chang RW, Dunlop DD. Population impact of arthritis on disability in older adults. Arthritis Rheum. Apr 15 2006;55(2):248–55. doi:10.1002/art.21842 16583415
6 Lawrence RC, Felson DT, Helmick CG, . Estimates of the prevalence of arthritis and other rheumatic conditions in the United States. Part II. Arthritis Rheum. Jan 2008;58(1):26–35. doi:10.1002/art.23176 18163497
7 Prevalence of doctor-diagnosed arthritis and arthritis-attributable activity limitation -- United States, 2007-2009. MMWR Morb Mortal Wkly Rep. Oct 8 2010;59(39):1261–5.20930703
8 Johnson VL, Hunter DJ. The epidemiology of osteoarthritis. Best Pract Res Clin Rheumatol. Feb 2014;28(1):5–15. doi:10.1016/j.berh.2014.01.004 24792942
9 Deshpande BR, Katz JN, Solomon DH, . Number of Persons With Symptomatic Knee Osteoarthritis in the US: Impact of Race and Ethnicity, Age, Sex, and Obesity. Arthritis Care Res (Hoboken). Dec 2016;68(12):1743–1750. doi:10.1002/acr.22897 27014966
10 Long H, Liu Q, Yin H, . Prevalence Trends of Site-Specific Osteoarthritis From 1990 to 2019: Findings From the Global Burden of Disease Study 2019. Arthritis Rheumatol. Jul 2022;74(7):1172–1183. doi:10.1002/art.42089 35233975
11 Litwic A, Edwards MH, Dennison EM, Cooper C. Epidemiology and burden of osteoarthritis. Br Med Bull. 2013;105:185–99. doi:10.1093/bmb/lds038 23337796
12 Urwin M, Symmons D, Allison T, . Estimating the burden of musculoskeletal disorders in the community: the comparative prevalence of symptoms at different anatomical sites, and the relation to social deprivation. Ann Rheum Dis. Nov 1998;57(11):649–55. doi:10.1136/ard.57.11.649 9924205
13 Uden H, Boesch E, Kumar S. Plantar fasciitis - to jab or to support? A systematic review of the current best evidence. J Multidiscip Healthc. 2011;4:155–64. doi:10.2147/jmdh.S20053 21655342
14 Culvenor AG, Øiestad BE, Hart HF, Stefanik JJ, Guermazi A, Crossley KM. Prevalence of knee osteoarthritis features on magnetic resonance imaging in asymptomatic uninjured adults: a systematic review and meta-analysis. Br J Sports Med. Oct 2019;53(20):1268–1278. doi:10.1136/bjsports-2018-099257 29886437
15 Bannuru RR, Schmid CH, Kent DM, Vaysbrot EE, Wong JB, McAlindon TE. Comparative effectiveness of pharmacologic interventions for knee osteoarthritis: a systematic review and network meta-analysis. Ann Intern Med. Jan 6 2015;162(1):46–54. doi:10.7326/m14-1231 25560713
16 Noorduyn JCA, Glastra van Loon T, van de Graaf VA, . Functional Outcomes of Arthroscopic Partial Meniscectomy Versus Physical Therapy for Degenerative Meniscal Tears Using a Patient-Specific Score: A Randomized Controlled Trial. Orthop J Sports Med. Oct 2020;8(10):2325967120954392. doi:10.1177/2325967120954392 33195707
17 Wijn SRW, Hannink G, Østerås H, . Arthroscopic partial meniscectomy vs non-surgical or sham treatment in patients with MRI-confirmed degenerative meniscus tears: a systematic review and meta-analysis with individual participant data from 605 randomised patients. Osteoarthritis Cartilage. May 2023;31(5):557–566. doi:10.1016/j.joca.2023.01.002 36646304
18 Distel LM, Best TM. Prolotherapy: a clinical review of its role in treating chronic musculoskeletal pain. Pm r. Jun 2011;3(6 Suppl 1):S78–81. doi:10.1016/j.pmrj.2011.04.003 21703585
19 Hackett GS. Ligament and tendon relaxation treated by prolotherapy. 1958:
20 DistillerSR. DistillerSR Inc. https://www.distillersr.com/
21 Cochrane Handbook for Systematic Reviews of Interventions. Updated August 22, 2023. https://training.cochrane.org/handbook
22 Sterne JAC, Savovic J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. Aug 28 2019;366:14898. doi:10.1136/bmj.l4898
23 Sterne JA, Hernan MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. Oct 12 2016;355:i4919. doi:10.1136/bmj.i4919 27733354
24 Moola S MZ, Tufanaru C, Aromataris E, Sears K, Sfetcu R, Currie M, Qureshi R, Mattis P, Lisy K, Mu P-F. Chapter 7: Systematic reviews of etiology and risk. In: Aromataris E MZ, ed. JBI Manual for Evidence Synthesis. JBI; 2020. https://synthesismanual.jbi.global
25 Salehi R, Valizadeh L, Negahban H, Karimi M, Goharpey S, Shahali S. The Western Ontario and McMaster Universities Osteoarthritis, Lequesne Algofunctional index, Arthritis Impact Measurement Scale-short form, and Visual Analogue Scale in patients with knee osteoarthritis: responsiveness and minimal clinically important differences. Disabil Rehabil. Jun 2023;45(13):2185–2191. doi:10.1080/09638288.2022.2084776 35695001
26 Angst F, Benz T, Lehmann S, Aeschlimann A, Angst J. Multidimensional minimal clinically important differences in knee osteoarthritis after comprehensive rehabilitation: a prospective evaluation from the Bad Zurzach Osteoarthritis Study. RMD Open. 2018;4(2):e000685. doi:10.1136/rmdopen-2018-000685 30402264
27 Martín-Fernández J, García-Maroto R, Sánchez-Jiménez FJ, . Validation of the Spanish version of the Oxford knee score and assessment of its utility to characterize quality of life of patients suffering from knee osteoarthritis: a multicentric study. Health Qual Life Outcomes. Sep 29 2017;15(1):186. doi:10.1186/s12955-017-0761-2 28962613
28 Mills KA, Naylor JM, Eyles JP, Roos EM, Hunter DJ. Examining the Minimal Important Difference of Patient-reported Outcome Measures for Individuals with Knee Osteoarthritis: A Model Using the Knee Injury and Osteoarthritis Outcome Score. J Rheumatol. Feb 2016;43(2):395–404. doi:10.3899/jrheum.150398 26773118
29 Hernandez-Sanchez S, Hidalgo MD, Gomez A. Responsiveness of the VISA-P scale for patellar tendinopathy in athletes. Br J Sports Med. Mar 2014;48(6):453–7. doi:10.1136/bjsports-2012-091163 23012320
30 Salaffi F, Stancati A, Silvestri CA, Ciapetti A, Grassi W. Minimal clinically important changes in chronic musculoskeletal pain intensity measured on a numerical rating scale. Eur J Pain. Aug 2004;8(4):283–91. doi:10.1016/j.ejpain.2003.09.004 15207508
31 Martin RL, Irrgang JJ, Burdett RG, Conti SF, Van Swearingen JM. Evidence of validity for the Foot and Ankle Ability Measure (FAAM). Foot Ankle Int. Nov 2005;26(11):968–83. doi:10.1177/107110070502601113 16309613
32 Franchignoni F, Vercelli S, Giordano A, Sartorio F, Bravini E, Ferriero G. Minimal clinically important difference of the disabilities of the arm, shoulder and hand outcome measure (DASH) and its shortened version (QuickDASH). J Orthop Sports Phys Ther. Jan 2014;44(1):30–9. doi:10.2519/jospt.2014.4893 24175606
33 Paul A, Lewis M, Shadforth MF, Croft PR, Van Der Windt DA, Hay EM. A comparison of four shoulder-specific questionnaires in primary care. Ann Rheum Dis. Oct 2004;63(10):1293–9. doi:10.1136/ard.2003.012088 15361390
34 Poltawski L, Watson T. Measuring clinically important change with the Patient-rated Tennis Elbow Evaluation. Hand Therapy. 2011/09/01 2011;16(3):52–57. doi:10.1258/ht.2011.011013
35 Monticone M, Baiardi P, Vanti C, . Responsiveness of the Oswestry Disability Index and the Roland Morris Disability Questionnaire in Italian subjects with sub-acute and chronic low back pain. Eur Spine J. Jan 2012;21(1):122–9. doi:10.1007/s00586-011-1959-3 21823035
36 Díaz-Arribas MJ, Fernández-Serrano M, Royuela A, . Minimal Clinically Important Difference in Quality of Life for Patients With Low Back Pain. Spine (Phila Pa 1976). Dec 15 2017;42(24):1908–1916. doi:10.1097/brs.0000000000002298 28658040
37 van der Roer N, Ostelo RW, Bekkering GE, van Tulder MW, de Vet HC. Minimal clinically important change for pain intensity, functional status, and general health status in patients with nonspecific low back pain. Spine (Phila Pa 1976). Mar 1 2006;31(5):578–82. doi:10.1097/01.brs.0000201293.57439.47 16508555
38 metafor: Meta-Analysis Package for R. https://cran.rproject.org/web/packages/metafor/index.html
39 Santesso N, Glenton C, Dahm P, . GRADE guidelines 26: informative statements to communicate the findings of systematic reviews of interventions. J Clin Epidemiol. Mar 2020;119:126–135. doi:10.1016/j.jclinepi.2019.10.014 31711912
40 GRADEpro GDT. https://www.gradepro.org/
41 Guyatt GH, Oxman AD, Kunz R, . GRADE guidelines 6. Rating the quality of evidence-imprecision. J Clin Epidemiol. Dec 2011;64(12):1283–93. doi:10.1016/j.jclinepi.2011.01.012 21839614
42 Rezasoltani Z, Taheri M, Mofrad MK, Mohajerani SA. Periarticular dextrose prolotherapy instead of intra-articular injection for pain and functional improvement in knee osteoarthritis. Journal of pain research. 2017;10:1179–1187. doi:10.2147/JPR.S127633 28553139
43 Hsieh R-L, Lee W-C. Effects of Intra-articular Coinjections of Hyaluronic Acid and Hypertonic Dextrose on Knee Osteoarthritis: A Prospective, Randomized, Double-Blind Trial. Archives of physical medicine and rehabilitation. 2022;103(8):1505–1514. doi:10.1016/j.apmr.2022.04.001 35439521
44 Reeves KD, Hassanein K. Randomized prospective double-blind placebo-controlled study of dextrose prolotherapy for knee osteoarthritis with or without ACL laxity. Alternative therapies in health and medicine. 2000;6(2):68–80.10710805
45 Sit RWS, Wu RWK, Rabago D, . Efficacy of Intra-Articular Hypertonic Dextrose (Prolotherapy) for Knee Osteoarthritis: A Randomized Controlled Trial. Annals of family medicine. 2020;18(3):235–242. doi:10.1370/afm.2520 32393559
46 Mruthyunjaya, Singh SP, Sundaresh S, Adarsh T. EFFECTIVE NONSURGICAL MANAGEMENT OF EARLY OSTEOARTHRITIS OF THE KNEE JOINT IN A TERTIARY CARE HOSPITAL - A PROSPECTIVE SINGLE-BLIND RANDOMIZED COMPARATIVE STUDY. Journal of Musculoskeletal Research. 2023;26(1):2350002. doi:10.1142/S0218957723500021
47 Pishgahi A, Abolhasan R, Shakouri SK, . Effect of Dextrose Prolotherapy, Platelet Rich Plasma and Autologous Conditioned Serum on Knee Osteoarthritis: A Randomized Clinical Trial. Iranian journal of allergy, asthma, and immunology. 2020;19(3):243–252. doi:10.18502/ijaai.v19i3.3452 32615658
48 Rahimzadeh P, Imani F, Faiz SHR, Entezary SR, Zamanabadi MN, Alebouyeh MR. The effects of injecting intra-articular platelet-rich plasma or prolotherapy on pain score and function in knee osteoarthritis. Clinical interventions in aging. 2018;13:73–79. doi:10.2147/CIA.S147757 29379278
49 Farpour HR, Fereydooni F. Comparative effectiveness of intra-articular prolotherapy versus peri-articular prolotherapy on pain reduction and improving function in patients with knee osteoarthritis: A randomized clinical trial. Electronic physician. 2017;9(11):5663–5669. doi:10.19082/5663 29403602
50 Babaeian Z, Farpour H, Mostaghni E, Vasaghi A, Nasiri A, Arjmand H. A Comparative Study of Short-Term Efficacy of Intra-articular Hypertonic Saline and Hypertonic Dextrose Prolotherapy in Knee Osteoarthritis: A Randomized Controlled Trial (RCT). Article. J Rehabilit Sci Res. 2022;9(2):60–64. doi:10.30476/JRSR.2022.90605.1150
51 Hashemi M, Jalili P, Mennati S, . The Effects of Prolotherapy With Hypertonic Dextrose Versus Prolozone (Intraarticular Ozone) in Patients With Knee Osteoarthritis. Anesthesiology and pain medicine. 2015;5(5):e27585. doi:10.5812/aapm.27585 26587401
52 Rahimzadeh P, Imani F, Faiz SHR, Entezary SR, Nasiri AA, Ziaeefard M. Investigation the efficacy of intra-articular prolotherapy with erythropoietin and dextrose and intra-articular pulsed radiofrequency on pain level reduction and range of motion improvement in primary osteoarthritis of knee. Journal of research in medical sciences : the official journal of Isfahan University of Medical Sciences. 2014;19(8):696–702.25422652
53 Rezasoltani Z, Azizi S, Najafi S, Sanati E, Dadarkhah A, Abdorrazaghi F. Physical therapy, intra-articular dextrose prolotherapy, botulinum neurotoxin, and hyaluronic acid for knee osteoarthritis: randomized clinical trial. International journal of rehabilitation research Internationale Zeitschrift fur Rehabilitationsforschung Revue internationale de recherches de readaptation. 2020;43(3):219–227. doi:10.1097/MRR.0000000000000411 32776763
54 Hosseini B, Taheri M, Pourroustaei Ardekani R, Moradi S, Kazempour Mofrad M. Periarticular hypertonic dextrose vs intraarticular hyaluronic acid injections: a comparison of two minimally invasive techniques in the treatment of symptomatic knee osteoarthritis. Open access rheumatology : research and reviews. 2019;11:269–274. doi:10.2147/OARRR.S215576 31819680
55 Taormina D, Abdallah HY, Venkataramanan R, . Stability and sorption of FK 506 in 5% dextrose injection and 0.9% sodium chloride injection in glass, polyvinyl chloride, and polyolefin containers. American journal of hospital pharmacy. 1992;49(1):119–22.
56 Ozturk MU, Baygutalp F. A comparative analysis of prolotherapy efficacy in patients with knee osteoarthritis across varied dextrose concentrations. Clinical rheumatology. 2023;42(12):3321–3331. doi:10.1007/s10067-023-06723-4 37540383
57 Soliman D, Sherif NM, Omar OH, el Zohiery A. Healing effects of prolotherapy in treatment of knee osteoarthritis healing effects of prolotherapy in treatment of knee osteoarthritis. Egyptian Rheumatology and Rehabilitation. 04/01 2016;43:47. doi:10.4103/1110-161X.181858
58 Baygutalp F, Çelik M, Öztürk MU, Yayık AM, Ahıskalıoğlu A. Comparison of the efficacy of dextrose prolotherapy and ozone in patients with knee osteoarthritis: A randomized cross-sectional study. Article. Appl Sci. 2021;11(21)9991. doi:10.3390/app11219991
59 Sert AT, Sen EI, Esmaeilzadeh S, Ozcan E. The Effects of Dextrose Prolotherapy in Symptomatic Knee Osteoarthritis: A Randomized Controlled Study. Journal of alternative and complementary medicine (New York, NY). 2020;26(5):409–417. doi:10.1089/acm.2019.0335
60 Bayat M, Hojjati F, Boland Nazar NS, Modabberi M, Rahimi MS. Comparison of Dextrose Prolotherapy and Triamcinolone Intraarticular Injection on Pain and Function in Patients with Knee Osteoarthritis - A Randomized Clinical Trial. Anesthesiology and pain medicine. 2023;13(2):e134415. doi:10.5812/aapm-134415 37601963
61 Dumais R, Benoit C, Dumais A, . Effect of regenerative injection therapy on function and pain in patients with knee osteoarthritis: a randomized crossover study. Pain medicine (Malden, Mass). 2012;13(8):990–9. doi:10.1111/j.1526-4637.2012.01422.x 22759069
62 Yildiz KM, Guler H, Ogut H, Yildizgoren MT, Turhanoglu AD. A comparison between hypertonic dextrose prolotherapy and conventional physiotherapy in patients with knee osteoarthritis. Medicine international. 2023;3(5):45. doi:10.3892/mi.2023.105 37745156
63 Rabago D, Patterson JJ, Mundt M, . Dextrose prolotherapy for knee osteoarthritis: a randomized controlled trial. Annals of family medicine. 2013;11(3):229–37. Erratum in: Ann Fam Med. 2013 Sep-Oct;11(5):480 Comment in: J Fam Pract. 2014 Apr;63(4):206–8 PMID: 24905123 [https://www.ncbi.nlm.nih.gov/pubmed/24905123]. doi:10.1370/afm.1504 23690322
64 Waluyo Y, Budu, Bukhari A, . Changes in levels of cartilage oligomeric proteinase and urinary C-terminal telopeptide of type II collagen in subjects with knee osteoarthritis after dextrose prolotherapy: A randomized controlled trial. Journal of rehabilitation medicine. 2021;53(5):jrm00196. doi:10.2340/16501977-2835 33904585
65 Karakilic GD, Aras M, Buyuk F, Bakirci ES. Prolotherapy Versus Phonophoresis and Corticosteroid Injections for the Treatment of Plantar Fasciitis: A Randomized, Double-Blind Clinical Trial. The Journal of foot and ankle surgery : official publication of the American College of Foot and Ankle Surgeons. 2023;doi:10.1053/j.jfas.2023.04.010
66 Ersen O, Koca K, Akpancar S, . A randomized-controlled trial of prolotherapy injections in the treatment of plantar fasciitis. Turkish journal of physical medicine and rehabilitation. 2018;64(1):59–65. doi:10.5606/tftrd.2018.944 31453490
67 Kesikburun S, Uran San A, Kesikburun B, Aras B, Yasar E, Tan AK. Comparison of Ultrasound-Guided Prolotherapy Versus Extracorporeal Shock Wave Therapy in the Treatment of Chronic Plantar Fasciitis: A Randomized Clinical Trial. The Journal of foot and ankle surgery : official publication of the American College of Foot and Ankle Surgeons. 2022;61(1):48–52. doi:10.1053/j.jfas.2021.06.007 34266721
68 Mansiz-Kaplan B, Nacir B, Pervane-Vural S, Duyur-Cakit B, Genc H. Effect of Dextrose Prolotherapy on Pain Intensity, Disability, and Plantar Fascia Thickness in Unilateral Plantar Fasciitis: A Randomized, Controlled, Double-Blind Study. American journal of physical medicine & rehabilitation. 2020;99(4):318–324. Comment in: Am J Phys Med Rehabil. 2020 Nov;99(11):e131–e132 PMID: 31860590 [https://www.ncbi.nlm.nih.gov/pubmed/31860590]. doi:10.1097/PHM.0000000000001330 31738283
69 Eua, Aşkın A, Tosun A. Is hypertonic dextrose injection effective in the treatment of plantar fasciitis: A clinical randomized study. The Medical bulletin. 12/01 2018;56:102–108.
70 Raissi G, Arbabi A, Rafiei M, . Ultrasound-Guided Injection of Dextrose Versus Corticosteroid in Chronic Plantar Fasciitis Management: A Randomized, Double-Blind Clinical Trial. Foot & ankle specialist. 2023;16(1):9–19. doi:10.1177/1938640020980924 33461323
71 Asheghan M, Hashemi SE, Hollisaz MT, Roumizade P, Hosseini SM, Ghanjal A. Dextrose prolotherapy versus radial extracorporeal shock wave therapy in the treatment of chronic plantar fasciitis: A randomized, controlled clinical trial. Foot and ankle surgery : official journal of the European Society of Foot and Ankle Surgeons. 2021;27(6):643–649. doi:10.1016/j.fas.2020.08.008 32919897
72 Kim E, Lee JH. Autologous platelet-rich plasma versus dextrose prolotherapy for the treatment of chronic recalcitrant plantar fasciitis. PM & R : the journal of injury, function, and rehabilitation. 2014;6(2):152–8. doi:10.1016/j.pmrj.2013.07.003
73 Lin L-C, Lee Y-H, Chen Y-W, . Comparison Clinical Effects of Hypertonic Dextrose and Steroid Injections on Chronic Subacromial Bursitis: A Double-Blind Randomized Controlled Trial. American journal of physical medicine & rehabilitation. 2023;102(10):867–872. doi:10.1097/PHM.0000000000002232 36897810
74 Lin C-L, Chen Y-W, Wu C-W, Liou T-H, Huang S-W. Effect of Hypertonic Dextrose Injection on Pain and Shoulder Disability in Patients with Chronic Supraspinatus Tendinosis: A Randomized Double-Blind Controlled Study. Archives of physical medicine and rehabilitation. 2022;103(2):237–244. doi:10.1016/j.apmr.2021.07.812 34610286
75 Chang Y-J, Chang F-H, Hou P-H, Tseng K-H, Lin Y-N. Effects of Hyperosmolar Dextrose Injection in Patients With Rotator Cuff Disease and Bursitis: A Randomized Controlled Trial. Archives of physical medicine and rehabilitation. 2021;102(2):245–250. doi:10.1016/j.apmr.2020.08.010 32926850
76 Lin C-L, Huang C-C, Huang S-W. Effects of hypertonic dextrose injection in chronic supraspinatus tendinopathy of the shoulder: a randomized placebo-controlled trial. European journal of physical and rehabilitation medicine. 2019;55(4):480–487. doi:10.23736/S1973-9087.18.05379-0 30543266
77 George J, Li SCn, Jaafar Z, Hamid MSA. Comparative Effectiveness of Ultrasound-Guided Intratendinous Prolotherapy Injection with Conventional Treatment to Treat Focal Supraspinatus Tendinosis. Scientifica. 2018;2018:4384159. doi:10.1155/2018/4384159 30057849
78 Abd Karim S, Hamid MS, Choong A, Ooi MY, Usman J. Effects of platelet-rich plasma and prolotherapy on supraspinatus tendinopathy: a double blind randomized clinical trial. The Journal of sports medicine and physical fitness. 2023;63(5):674–684. doi:10.23736/S0022-4707.22.14376-8 37132278
79 Sam N, Yusuf I, Idris I, . The level of ratio between matrix metalloproteinase-1 (MMP-1) and tissue inhibitor matrix metalloproteinase-1 (TIMP-1) after prolotherapy intervention and the functional outcome in patient with frozen shoulder: A randomized controlled trial. Medicine. 2023;102(30):e34356. doi:10.1097/MD.0000000000034356 37505166
80 Nasiri A, Mohamadi Jahromi LS, Vafaei MA, Parvin R, Fakheri MS, Sadeghi S. Comparison of the Effectiveness of Ultrasound-Guided Prolotherapy in Supraspinatus Tendon with Ultrasound-Guided Corticosteroid Injection of Subacromial Subdeltoid Bursa in Rotator Cuff-Related Shoulder Pain: A Clinical Trial Study. Advanced biomedical research. 2021;10:12. doi:10.4103/abr.abr_181_20 34195156
81 Kazempour Mofrad M, Rezasoltani Z, Dadarkhah A, Kazempour Mofrad R, Abdorrazaghi F, Azizi S. Periarticular Neurofascial Dextrose Prolotherapy Versus Physiotherapy for the Treatment of Chronic Rotator Cuff Tendinopathy: Randomized Clinical Trial. Journal of clinical rheumatology : practical reports on rheumatic & musculoskeletal diseases. 2021;27(4):136–142. doi:10.1097/RHU.0000000000001218 32975923
82 Sari A, Eroglu A. Comparison of ultrasound-guided platelet-rich plasma, prolotherapy, and corticosteroid injections in rotator cuff lesions. Journal of back and musculoskeletal rehabilitation. 2020;33(3):387–396. doi:10.3233/BMR-191519 31743987
83 Seven MM, Ersen O, Akpancar S, . Effectiveness of prolotherapy in the treatment of chronic rotator cuff lesions. Orthopaedics & traumatology, surgery & research : OTSR. 2017;103(3):427–433. doi:10.1016/j.otsr.2017.01.003
84 Cole B, Lam P, Hackett L, Murrell GAC. Ultrasound-guided injections for supraspinatus tendinopathy: corticosteroid versus glucose prolotherapy - a randomized controlled clinical trial. Shoulder & elbow. 2018;10(3):170–178. doi:10.1177/1758573217708199 29796104
85 Bertrand H, Reeves KD, Bennett CJ, Bicknell S, Cheng A-L. Dextrose Prolotherapy Versus Control Injections in Painful Rotator Cuff Tendinopathy. Archives of physical medicine and rehabilitation. 2016;97(1):17–25. doi:10.1016/j.apmr.2015.08.412 26301385
86 Creech-Organ JA, Szybist SE, Yurgil JL. Joint and Soft Tissue Injections. American family physician. 2023;108(2):151–158.37590853
87 Abbadi W, Kara Beit Z, Al-Khanati NM. Arthrocentesis, Injectable Platelet-Rich Plasma and Combination of Both Protocols of Temporomandibular Joint Disorders Management: A Single-Blinded Randomized Clinical Trial. Cureus. 2022;14(11):e31396. doi:10.7759/cureus.31396 36523721
88 Akcay S, Gurel Kandemir N, Kaya T, Dogan N, Eren M. Dextrose Prolotherapy Versus Normal Saline Injection for the Treatment of Lateral Epicondylopathy: A Randomized Controlled Trial. Journal of alternative and complementary medicine (New York, NY). 2020;26(12):1159–1168. doi:10.1089/acm.2020.0286
89 Ahadi T, Esmaeili Jamkarani M, Raissi GR, Mansoori K, Emami Razavi SZ, Sajadi S. Prolotherapy vs Radial Extracorporeal Shock Wave Therapy in the Short-term Treatment of Lateral Epicondylosis: A Randomized Clinical Trial. Pain medicine (Malden, Mass). 2019;20(9):1745–1749. Erratum in: Pain Med. 2019 Dec 1;20(12):2612 PMID: 30865767 [https://www.ncbi.nlm.nih.gov/pubmed/30865767]. doi:10.1093/pm/pny303 30698771
90 Rabago D, Lee KS, Ryan M, . Hypertonic dextrose and morrhuate sodium injections (prolotherapy) for lateral epicondylosis (tennis elbow): results of a single-blind, pilot-level, randomized controlled trial. American journal of physical medicine & rehabilitation. 2013;92(7):587–96. doi:10.1097/PHM.0b013e31827d695f 23291605
91 Scarpone M, Rabago DP, Zgierska A, Arbogast G, Snell E. The efficacy of prolotherapy for lateral epicondylosis: a pilot study. Clinical journal of sport medicine : official journal of the Canadian Academy of Sport Medicine. 2008;18(3):248–54. doi:10.1097/JSM.0b013e318170fc87 18469566
92 Deb D, Akoijam js, Bimol N, . Comparison between prolotherapy using 25% dextrose versus extracorporeal shock wave therapy in the management of pain and improvement of functional outcome in patients suffering from chronic lateral epicondylitis: a randomized controlled trial. International Journal of Research in Medical Sciences. 10/28 2020;8:4056. doi:10.18203/2320-6012.ijrms20204903
93 Ciftci YGD, Tuncay F, Kocak FA, Okcu M. Is Low-Dose Dextrose Prolotherapy as Effective as High-Dose Dextrose Prolotherapy in the Treatment of Lateral Epicondylitis? A Double-Blind, Ultrasound Guided, Randomized Controlled Study. Archives of physical medicine and rehabilitation. 2023;104(2):179–187. Comment in: Arch Phys Med Rehabil. 2023 Jul;104(7):1154–1155 PMID: 36990375 [https://www.ncbi.nlm.nih.gov/pubmed/36990375] Comment in: Arch Phys Med Rehabil. 2023 Jul;104(7):1155–1156 PMID: 36990377 [https://www.ncbi.nlm.nih.gov/pubmed/36990377]. doi:10.1016/j.apmr.2022.09.017 36243123
94 Bayat M, Raeissadat SA, Mortazavian Babaki M, Rahimi-Dehgolan S. Is Dextrose Prolotherapy Superior To Corticosteroid Injection In Patients With Chronic Lateral Epicondylitis?: A Randomized Clinical Trial. Orthopedic research and reviews. 2019;11:167–175. doi:10.2147/ORR.S218698 31819675
95 Kaya SS, Yardimci G, Goksu H, Genc H. Effects of splinting and three injection therapies (corticosteroid, autologous blood and prolotherapy) on pain, grip strength, and functionality in patients with lateral epicondylitis. Turkish journal of physical medicine and rehabilitation. 2022;68(2):205–213. doi:10.5606/tftrd.2022.8007 35989952
96 Apaydin H, Bazancir Z, Altay Z. Injection Therapy in Patients with Lateral Epicondylalgia: Hyaluronic Acid or Dextrose Prolotherapy? A Single-Blind, Randomized Clinical Trial. Journal of alternative and complementary medicine (New York, NY). 2020;26(12):1169–1175. doi:10.1089/acm.2020.0188
97 Gupta GK, Rani S, Shekhar D, Sahoo UK, Shekhar S. Comparative study to evaluate efficacy of prolotherapy using 25% dextrose and local corticosteroid injection in tennis elbow - A prospective study. Journal of family medicine and primary care. 2022;11(10):6345–6349. doi:10.4103/jfmpc.jfmpc_116_22
98 Yelland M, Rabago D, Ryan M, . Prolotherapy injections and physiotherapy used singly and in combination for lateral epicondylalgia: a single-blinded randomised clinical trial. BMC musculoskeletal disorders. 2019;20(1):509. doi:10.1186/s12891-019-2905-5 31679521
99 Yelland MJ, Glasziou PP, Bogduk N, Schluter PJ, McKernon M. Prolotherapy injections, saline injections, and exercises for chronic low-back pain: a randomized trial. Spine. 2004;29(1):9–16. Comment in: Spine (Phila Pa 1976). 2004 Aug 15;29(16):1839–40; author reply 1842-3 PMID: 15303037 [https://www.ncbi.nlm.nih.gov/pubmed/15303037] Comment in: Spine (Phila Pa 1976). 2004 Aug 15;29(16):1840–1; author reply 1842-3 PMID: 15303038 [https://www.ncbi.nlm.nih.gov/pubmed/15303038] Comment in: Spine (Phila Pa 1976). 2004 Aug 15;29(16):1841–2; author reply 1842-3 PMID: 15303039 [https://www.ncbi.nlm.nih.gov/pubmed/15303039] Comment in: Spine (Phila Pa 1976). 2004 Oct 1;29(19):2195; author reply 2195-6 PMID: 15454717 [https://www.ncbi.nlm.nih.gov/pubmed/15454717].14699269
100 Dechow E, Davies RK, Carr AJ, Thompson PW. A randomized, double-blind, placebo-controlled trial of sclerosing injections in patients with chronic low back pain. Rheumatology (Oxford, England). 1999;38(12):1255–9. Comment in: Rheumatology (Oxford). 2000 Aug;39(8):924–5 PMID: 10952754 [https://www.ncbi.nlm.nih.gov/pubmed/10952754] Comment in: Rheumatology (Oxford). 2000 Aug;39(8):925 PMID: 10952755 [https://www.ncbi.nlm.nih.gov/pubmed/10952755].10587555
101 Klein RG, Eek BC, DeLong WB, Mooney V. A randomized double-blind trial of dextrose-glycerine-phenol injections for chronic, low back pain. Journal of spinal disorders. 1993;6(1):23–33.8439713
102 Ongley MJ, Klein RG, Dorman TA, Eek BC, Hubert LJ. A new approach to the treatment of chronic low back pain. Lancet (London, England). 1987;2(8551):143–6.2439856
103 Jacks A, Barling T. Lumbosacral prolotherapy: A before-and-after study in an NHS setting. Article. International Musculoskeletal Medicine. 2012;34(1):7–12. doi:10.1179/1753615412Y.0000000002
104 Derby R, Eek B, Lee SH, Seo KS, Kim BJ. Comparison of intradiscal restorative injections and intradiscal electrothermal treatment (IDET) in the treatment of low back pain. Pain Physician. 2004;7(1):63–66.16868613
105 Yildirim T. Comparison of the effectiveness of prolotherapy and facet joint injection in the treatment of chronic low back pain: A retrospective study. Turkiye Klinikleri Journal of Medical Sciences. 2021;41(1):1–6. Kronik bel agrisinin tedavisinde proloterapi ile faset eklem enjeksiyonunun etkinliginin karsilastirilmasi: Retrospektif calisma. doi:10.5336/medsci.2020-80271
106 Raissi G, Ahadi T, Forogh B, . Corticosteroid Versus Dextrose Ultrasound-Guided Injection in the Treatment of Sacroiliac Joint Dysfunction: A Randomized Double-Blinded Clinical Trial. Article. J Iran Med Counc. 2022;5(4):668–676. doi:10.18502/jimc.v5i4.11340
107 Kim WM, Lee HG, Jeong CW, Kim CM, Yoon MH. A randomized controlled trial of intra-articular prolotherapy versus steroid injection for sacroiliac joint pain. Journal of alternative and complementary medicine (New York, NY). 2010;16(12):1285–90. doi:10.1089/acm.2010.0031
108 Elwerfelli A, Kalil A, Abdullah N. CLINICAL EVALUATION OF DEXTROSE PROLOTHERAPY FOR MANAGEMENT OF TEMPOROMANDIBULAR JOINT DISORDER. Alexandria Dental Journal. 12/01 2019;44:1–7. doi:10.21608/adjalexu.2019.63548
109 Fouda AA. Change of site of intra-articular injection of hypertonic dextrose resulted in different effects of treatment. The British journal of oral & maxillofacial surgery. 2018;56(8):715–718. doi:10.1016/j.bjoms.2018.07.022 30107954
110 Haggag MA, Al-Belasy FA, Said Ahmed WM. Dextrose prolotherapy for pain and dysfunction of the TMJ reducible disc displacement: A randomized, double-blind clinical study. Journal of cranio-maxillo-facial surgery : official publication of the European Association for Cranio-Maxillo-Facial Surgery. 2022;50(5):426–431. doi:10.1016/j.jcms.2022.02.009 35501215
111 Hassanien N, Kamel H, Rashed S. Dextrose Prolotherapy versus Low Level Laser Therapy (LLLT) for Management of Temporomandibular Joint Disorders (TMD): Clinical Randomized controlled Study. Egyptian Dental Journal. 01/01 2020;66:95–106. doi:10.21608/edj.2020.77519
112 Louw WF, Reeves KD, Lam SKH, Cheng A-L, Rabago D. Treatment of Temporomandibular Dysfunction With Hypertonic Dextrose Injection (Prolotherapy): A Randomized Controlled Trial With Long-term Partial Crossover. Mayo Clinic proceedings. 2019;94(5):820–832. doi:10.1016/j.mayocp.2018.07.023 30878157
113 Mahmoud N. Sodium hyaluronic acid, platelet rich plasma and dextrose prolotherapy in management of Temporo-mandibular joint internal derangement. A Comparative study. Egyptian Dental Journal. 04/01 2018;64:1055–1069. doi:10.21608/edj.2018.76957
114 Priyadarshini S, Gnanam A, Sasikala B, . Evaluation of prolotherapy in comparison with occlusal splints in treating internal derangement of the temporomandibular joint - A randomized controlled trial. Journal of cranio-maxillo-facial surgery : official publication of the European Association for Cranio-Maxillo-Facial Surgery. 2021;49(1):24–28. doi:10.1016/j.jcms.2020.11.004 33279397
115 Zarate MA, Frusso RD, Reeves KD, Cheng A-L, Rabago D. Dextrose Prolotherapy Versus Lidocaine Injection for Temporomandibular Dysfunction: A Pragmatic Randomized Controlled Trial. Journal of alternative and complementary medicine (New York, NY). 2020;26(11):1064–1073. doi:10.1089/acm.2020.0207
116 Arafat S, Elbaz M. ASSESSMENT OF THE THERAPEUTIC EFFECTS OF AUTOLOGOUS BLOOD VERSUS DEXTROSE PROLOTHERAPY FOR THE TREATMENT OF TEMPORO- MANDIBULAR JOINT HYPERMOBILITY. A RANDOMIZED PROSPECTIVE CLINICAL STUDY. Egyptian Dental Journal. 07/01 2019;65:2125–2131. doi:10.21608/edj.2019.72230
117 Bhargava D, Sivakumar B, Bhargava PG. A Comparative Preliminary Randomized Clinical Study to Evaluate Heavy Bupivacaine Dextrose Prolotherapy (HDP) and Autologous Blood Injection (ABI) for Symptomatic Temporomandibular Joint Hypermobility Disorder. Journal of maxillofacial and oral surgery. 2023;22(1):110–118. doi:10.1007/s12663-022-01738-x
118 Chhapane A, Wadde K, Sachdev SS, Barai S, Landge J, Wadewale M. Comparison of Autologous Blood Injection and Dextrose Prolotherapy in the Treatment of Chronic Recurrent Temporomandibular Dislocation: A Randomized Clinical Trial. Article. Journal of Maxillofacial and Oral Surgery. 2023;doi:10.1007/s12663-023-01848-0
119 Comert Kilic S, Gungormus M. Is dextrose prolotherapy superior to placebo for the treatment of temporomandibular joint hypermobility? A randomized clinical trial. International journal of oral and maxillofacial surgery. 2016;45(7):813–9. doi:10.1016/j.ijom.2016.01.006 26846795
120 Mustafa R, Gungormus M, Mollaoglu N. Evaluation of the Efficacy of Different Concentrations of Dextrose Prolotherapy in Temporomandibular Joint Hypermobility Treatment. The Journal of craniofacial surgery. 2018;29(5):e461–e465. doi:10.1097/SCS.0000000000004480 29533255
121 Pandey SK, Baidya M, Srivastava A, Garg H. Comparison of autologous blood prolotherapy and 25% dextrose prolotherapy for the treatment of chronic recurrent temporomandibular joint dislocation on the basis of clinical parameters: A retrospective study. National journal of maxillofacial surgery. 2022;13(3):398–404. doi:10.4103/njms.njms_509_21 36683930
122 Refai H, Altahhan O, Elsharkawy R. The efficacy of dextrose prolotherapy for temporomandibular joint hypermobility: a preliminary prospective, randomized, double-blind, placebo-controlled clinical trial. Journal of oral and maxillofacial surgery : official journal of the American Association of Oral and Maxillofacial Surgeons. 2011;69(12):2962–70. doi:10.1016/j.joms.2011.02.128 21757278
123 Saadat A, Khedr M, Saad K, Naguib A. Dextrose Prolotherapy in the Treatment of Recurrent Temporomandibular Joint Dislocation (clinical study). Egyptian Journal of Oral and Maxillofacial Surgery. 10/01 2018;9:157–162. doi:10.21608/omx.2018.5059.1016
124 Arafat ZAA, Abdullah AB, Makhlouf AO, Shatat ZA. Computed Guided Prolotherapy Versus Conventional Prolotherapy in The Treatment of TMJ Internal Derangement. Al-Azhar Assiut Dental Journal. 2024;
125 Babaei-Ghazani A, Eftekharsadat B, Soleymanzadeh H, ZoghAli M. Ultrasound Guided Pes Anserine Bursitis Injection Choices; Prolotherapy or Oxygen-Ozone or Corticosteroid: A Randomized Multicenter Clinical Trial. American journal of physical medicine & rehabilitation. 2023;doi:10.1097/PHM.0000000000002343
126 Hadianfard M, Safari B, Jahromi LSM. Comparative Effectiveness of the Corticosteroid Injection and Prolotherapy in Patients With Hallux Rigidus: A Clinical Trial. Article. Iran Rehabil J. 2023;21(1):127–134. doi:10.32598/irj.21.1.1837.1
127 Jahangiri A, Moghaddam FR, Najafi S. Hypertonic dextrose versus corticosteroid local injection for the treatment of osteoarthritis in the first carpometacarpal joint: a double-blind randomized clinical trial. Journal of orthopaedic science : official journal of the Japanese Orthopaedic Association. 2014;19(5):737–43. doi:10.1007/s00776-014-0587-2 25158896
128 Cho SI, Shin YA. Effect of rehabilitation and prolotherapy on pain and functional performance in patients with chronic patellar tendinopathy. Gazzetta Medica Italiana Archivio per le Scienze Mediche. 2017;176(6):330–337. doi:10.23736/S0393-3660.16.03339-8
129 Yelland MJ, Sweeting KR, Lyftogt JA, Ng SK, Scuffham PA, Evans KA. Prolotherapy injections and eccentric loading exercises for painful Achilles tendinosis: a randomised trial. British journal of sports medicine. 2011;45(5):421–8. doi:10.1136/bjsm.2009.057968 19549615
130 Gul D, Orscelik A, Akpancar S. Treatment of Osteoarthritis Secondary to Developmental Dysplasia of the Hip with Prolotherapy Injection versus a Supervised Progressive Exercise Control. Medical science monitor : international medical journal of experimental and clinical research. 2020;26:e919166. doi:10.12659/MSM.919166 32045406
131 Akpancar S, Gul D. Comparison of Platelet Rich Plasma and Prolotherapy in the Management of Osteochondral Lesions of the Talus: A Retrospective Cohort Study. Medical science monitor: international medical journal of experimental and clinical research. 2019;25:5640–5647. doi:10.12659/MSM.914111 31358724
132 Ustun I, Caglar S. Comparison of the effect of prolotherapy and paraffin wax for hand osteoarthritis. European review for medical and pharmacological sciences. 2023;27(20):9510–9520. doi:10.26355/eurrev_202310_34124 37916318
133 Abd Elghany SE, Al Ashkar DS, El-Barbary AM, . Regenerative injection therapy and repetitive transcranial magnetic stimulation in primary fibromyalgia treatment: A comparative study. Journal of back and musculoskeletal rehabilitation. 2019;32(1):55–62. doi:10.3233/BMR-181127 30149440
134 Senturk E, Sahin E, Serter S. Prolotherapy: An effective therapy for Tietze syndrome. Journal of back and musculoskeletal rehabilitation. 2017;30(5):975–978. doi:10.3233/BMR-159269 28505950
135 Wu Z, Tu X, Tu Z. Hyperosmolar dextrose injection for Osgood-Schlatter disease: a double-blind, randomized controlled trial. Archives of orthopaedic and trauma surgery. 2022;142(9):2279–2285. doi:10.1007/s00402-021-04223-1 34673998
136 Hooper RA, Hildebrand K, Westaway M, Freiheit E. Randomized controlled trial for the treatment of chronic dorsal wrist pain with dextrose prolotherapy. Article. International Musculoskeletal Medicine. 2011;33(3):100–106. doi:10.1179/1753615411Y.0000000011
137 Altman RD, Devji T, Bhandari M, Fierlinger A, Niazi F, Christensen R. Clinical benefit of intra-articular saline as a comparator in clinical trials of knee osteoarthritis treatments: A systematic review and meta-analysis of randomized trials. Semin Arthritis Rheum. Oct 2016;46(2):151–159. doi:10.1016/j.semarthrit.2016.04.003 27238876
138 Englund M, Turkiewicz A. Pain in clinical trials for knee osteoarthritis: estimation of regression to the mean. Lancet Rheumatol. Jun 2023;5(6):e309–e311. doi:10.1016/s2665-9913(23)00090-5 38251596
139 Zhang W, Robertson J, Jones AC, Dieppe PA, Doherty M. The placebo effect and its determinants in osteoarthritis: meta-analysis of randomised controlled trials. Ann Rheum Dis. Dec 2008;67(12):1716–23. doi:10.1136/ard.2008.092015 18541604
140 Aydın M, Arıkan M, Toğral G, Varış O, Aydın G. Viscosupplementation of the knee: Three cases of acute Pseudoseptic Arthritis with painful and irritating complications and a literature review. Eur J Rheumatol. Mar 2017;4(1):59–62. doi:10.5152/eurjrheum.2016.15075 28293455