# ACKNOWLEDGMENTS

The authors are grateful to Becky Baltich Nelson, MLS, MS for literature searching, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Timothy Dawson, MD
  Deputy Executive Director, PMOP
  VA Puget Sound Health Care System, Seattle, Washington
- Joel Scholten, MD
  National Director, Physical Medicine and Rehabilitation
  VA Washington DC Healthcare System, Washington, DC

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Peggy Kim, MD
  Associate Chief of Staff, Education/DEO
  VA Puget Sound Health Care System, Seattle, Washington
- Michael Campian, DO
  Staff Physician, PM&R
  VA Salt Lake City Healthcare System, Salt Lake City, Utah
- Penny Jensen, DNP
  Associate Director, National APRN Practice
  Liaison for APRN National Policy
  VA Central Office, Washington, DC
- Aram Mardian, MD
  Staff Physician, Ambulatory Care
  VA Phoenix Health Care System, Phoenix, Arizona
- Robert Worthing, MD
  Medical Director, PM&R MSK
  Lexington VA Healthcare System, Lexington, Kentucky
- Jennifer Martin, PharmD
  Deputy Chief Consultant, Pharmacy
  Pharmacy Benefits Management, Department of Veterans Affairs
- Ben Jensen, MD
  Staff Physician, Rehab
  VA Salt Lake City Healthcare System, Salt Lake City, Utah
- Franz Macedo, DO
  Director, REC-ICC
  Minneapolis VA Health Care System, Minneapolis, MN
- Myron Senchysak, DO
  Interventional Pain Medicine Physician Point of Contact
  Pain, Pain Medicine Facility Consultant
  VA Clarksburg Healthcare System, Clarksburg, West Virginia