# ABBREVIATIONS TABLE

Abbreviation: Definition
ACL: Anterior cruciate ligament
ACR: American College of Radiology
ACR: American College of Rheumatology
ACS: Autologous conditioned serum
ADD: Anterior displacement difference
ADL: Activities of daily living
AE: Adverse effect/event
AOS: Ankle Osteoarthritis Scale
ASES: American Shoulder and Elbow Surgeons Standardized Shoulder Assessment
BMI: Body mass index
cc: Cubic centimeter
COE: Certainty of evidence
DASH: Disabilities of the Arm, Shoulder, and Hand Questionnaire
DDH: Development dysplasia of the hip
DHI: Duruoz Hand Index
dl: Deciliter
DMSO: Dimethyl sulfoxide
DPQ: Dallas Pain Questionnaire
ESWT: Extracorporeal shockwave therapy
EuroQol-5D: European Quality of Life-5 Dimensions
FAAM-ADL: Foot and Ankle Ability Measure-Activities of Daily Living
FAAM-S: Foot and Ankle Ability Measure-Sports
FAOS: Foot and Ankle Outcome Score
FFI: Foot Function Index
FIQR: Revised Fibromyalgia Impaction Questionnaire
G: Gauge
GRADE: Grading of Recommendations, Assessment, Development, and Evaluation
HA: Hyaluronic acid
HAQ-DI: Health Assessment Questionnaire Disability Index
HD: Hypertonic dextrose
HP: Hot pack
Hz: Hertz
IDET: Intradiscal electrothermal treatment
IU: International units
kg: Kilogram
KL: Kellgren-Lawrence
KOA: Knee osteoarthritis
KOOS: Knee Injury and Osteoarthritis Outcome Score
KPS: Knee Pain Scale
LDLPC: Left dorsolateral prefrontal cortex
m: Meters
MCID: Minimal clinically important difference
mg: Milligram
MHz: Megahertz
ml: Milliliter
mm: Millimeters
mo: Month(s)
mOsm: Osmotic concentration
MOXFQ: Manchester-Oxford Foot Questionnaire
MRI: Magnetic resonance imaging
NA: Not applicable
NR: Not reported
NRS: Numeric rating scale
NS: Not significant
NSAIDs: Non-steroid anti-inflammatory drugs
OA: Osteoarthritis
ODI: Oswestry Disability Index
OKS: Oxford Knee Score
OSD: Osgood-Schlatter Disease
PRP: Platelet rich plasma
PrT: Prolotherapy
PRTEE: Patient-Rated Tennis Elbow Evaluation
PT: Physical therapy
PWRE: Patient Rated Wrist Evaluation
QoL: Quality of life
Quick DASH: Shortened version of DASH
RA: Rheumatoid arthritis
RC: Rotator cuff
RCT: Randomized controlled trial
RMDQ: Roland-Morris Disability Questionnaire
RoB: Risk of bias
ROM: Range of motion
rTMS: Repetitive transcranial magnetic stimulation
s: Seconds
SD: Standard deviation
SF-36: Short Form Survey (36 items)
SLE: Systemic lupus erythematosus
SMD: Standardized mean difference
SPADI: Shoulder Pain and Disability Index
TENS: Transcutaneous electrical nerve stimulation
THA: Total hip arthroplasty
TUG: Timed Up and Go
U: Units
US: ultrasound
VAS: Visual analog scale
VISA-A: Victorian Institute of Sport Assessment-Achilles
VISA-P: Victorian Institute of Sport Assessment (VISA) Questionnaire, Patellar Tendon
vol: Volume
WDI: Waddell Disability Index
wk: Week(s)
WOMAC: Western Ontario and McMaster Universities Arthritis index
WORC: Western Ontario Rotator Cuff index
yr: Year