# DISCUSSION

There are substantial limitations to the evidence on efficacy and harms of dextrose prolotherapy for musculoskeletal pain conditions. Most available studies (83%) were very small with fewer than 100 participants, and nearly half (48%) were rated high risk of bias. Studies varied greatly in dextrose concentrations employed, injection technique, cointerventions, and comparators. The most commonly assessed outcomes were pain-related functioning and intensity, while fewer studies reported on physical performance, health-related quality of life, and adverse events. Only 2 studies (neither in the US) examined costs for health care systems, and none reported costs or treatment burden for patients.

In most studies, efficacy outcomes improved for all arms (intervention and comparators) over time. Intra-articular dextrose prolotherapy for knee osteoarthritis probably has little to no additional benefit for pain-related functioning and physical performance compared with normal saline injection (moderate COE). Combined intra- and extra-articular dextrose prolotherapy for knee osteoarthritis may improve pain-related functioning compared with either PT/home exercise or normal saline injection, but only at long-term follow-up (low COE). For plantar fasciitis and lateral elbow tendinopathy, dextrose prolotherapy may improve pain-related functioning, compared with normal saline injection (low COE). For shoulder pain due to mixed bursitis and rotator cuff pathology, dextrose prolotherapy probably results in worse physical performance outcomes, compared with corticosteroid injections. The evidence was uncertain for other efficacy outcomes and other comparators across these pain conditions, as well as for adverse events for all conditions (very low COE). Summary findings are presented below by individual musculoskeletal pain conditions (for comparisons with at least 2 available studies).

## SUMMARY OF KEY FINDINGS

### Knee Osteoarthritis

- Intra-articular dextrose prolotherapy probably had little to no benefit for pain-related functioning and physical performance at short-, medium-, and long-term follow-up, compared with normal saline injection (moderate COE). It also had little to no benefit for health-related quality of life, compared with normal saline injection (high COE).
- Intra-articular dextrose prolotherapy may have little to no benefit for pain-related functioning at short-, medium-, and long-term follow-up, compared with ozone injection (low COE).
- The evidence was very uncertain on the benefits of intra-articular dextrose prolotherapy for pain-related functioning at short- and long-term follow-up, compared with PRP (very low COE). It also may have little to no effect at medium term (low COE).
- Combined intra-articular and extra-articular dextrose prolotherapy may improve pain-related functioning and physical performance at long-term follow-up, compared with PT/home exercise programs (low COE). But at short- and medium-term follow-up, the evidence is very uncertain for these outcomes (very low COE).
- Combined intra-articular and extra-articular dextrose prolotherapy may improve pain-related functioning at long-term follow-up, compared with normal saline (low COE), but the evidence is very uncertain at short and medium term (very low COE).
- The evidence was also very uncertain on adverse effects of dextrose prolotherapy versus any comparator (very low COE).

### Plantar Fasciitis

- Dextrose prolotherapy may improve pain-related functioning at short- and medium-term follow-up, compared with normal saline, but may have little to no benefit compared with ESWT (low COE).
- The evidence was very uncertain on the effects of dextrose prolotherapy on pain-related functioning (very low COE), but it may have no to little benefit for health-related quality of life (low COE), compared with corticosteroid injection.
- The evidence was very uncertain on adverse effects of dextrose prolotherapy (very low COE).

### Shoulder Pain (Due to Mixed Bursitis and Rotator Cuff Pathology)

- The evidence was very uncertain on the effect of dextrose prolotherapy on pain-related functioning at short- and medium-term follow-up (very low COE), and it may have little to no benefit for physical performance (low COE), compared with normal saline injection.
- The evidence was also very uncertain on the effect of dextrose prolotherapy on pain-related functioning at short- and medium-term follow-up (very low COE), and it probably resulted in worse physical performance (moderate COE), compared with corticosteroid injection.
- The evidence was very uncertain on the benefits of dextrose prolotherapy for pain-related functioning at short- and medium-term (very low COE) follow-up, compared with PT/home exercise. For physical performance, findings differed at short, medium, and long-term (low and very low COE).
- The evidence was very uncertain on adverse effects of dextrose prolotherapy (very low COE).

### Lateral Elbow Tendinopathy

- Dextrose prolotherapy may improve pain-related functioning at short- and medium-term follow-up, compared with normal saline injection (low COE), but the evidence was uncertain or suggested little to no benefit for physical performance (very low or low COE).
- The evidence was also very uncertain for pain-related functioning, compared with corticosteroid injection (very low COE), and dextrose prolotherapy may have little to no benefit for physical performance at short- and long-term follow-up (low COE).
- The evidence was very uncertain for pain-related functioning and physical performance at short- and medium-term follow-up, compared with ESWT (very low COE), but dextrose prolotherapy may improve physical performance in the long term (low COE).
- The evidence was very uncertain on adverse effects of dextrose prolotherapy (very low COE).

### Chronic Low Back Pain

- For non-specific low back pain, the evidence was very uncertain on the benefits of dextrose prolotherapy for pain-related functioning (very low COE), and it may have little to no benefit for physical performance (low COE), compared with normal saline injection.
- For back pain related to sacroiliac joint dysfunction, the evidence was very uncertain on the benefits of dextrose prolotherapy for pain-related functioning (very low COE), compared with corticosteroid injection.
- The evidence was very uncertain on adverse effects of dextrose prolotherapy (very low COE).

### Temporomandibular Joint Dysfunction and Pain

- For TMJ disorders with restricted or normal mobility at baseline, the evidence was very uncertain on the benefits and adverse effects of dextrose prolotherapy, compared with normal saline (very low COE).
- For TMJ disorders with hypermobility at baseline, the evidence was very uncertain on the benefits and adverse effects of dextrose prolotherapy, compared with normal saline or autologous blood injection (very low COE).

## LIMITATIONS

When synthesizing the evidence for each musculoskeletal pain condition, we grouped together studies based primarily on comparator characteristics and thus included a variety of dextrose concentrations and injection locations in the dextrose prolotherapy arms. We also grouped a variety of PT-provided treatments and home exercise programs together as a similar comparator. To better assess the clinical importance of findings, we sought and used published MCID to determine whether there were meaningful differences in effects, but for a substantial number of outcomes measures, we were unable to locate published MCID values. In those situations, we used statistical significance, which is subject to the appropriateness of analyses reported by authors. We also limited eligibility to English-language studies, and thus did not include or review non-English studies. However, a large proportion of identified studies were conducted in countries where English is not the primary language, so it appears this did not substantially limit our ability to locate relevant evidence.

## EVIDENCE GAPS AND FUTURE RESEARCH

The evidence on efficacy and safety of dextrose prolotherapy for musculoskeletal disorders is limited by small sample sizes for most studies and substantial methodological concerns (nearly half were rated high, serious, or critical RoB). There was considerable variation in intervention characteristics, cointerventions, study populations, and choice of outcome measures across studies. To provide clinically relevant interpretations, we assessed between-group differences using published MCID whenever available. The evidence suggests that efficacy of prolotherapy may be condition specific since there is probably little to no benefit for knee osteoarthritis (for intra-articular injection compared with normal saline), but for conditions like lateral elbow tendinopathy and plantar fasciitis, there may be some benefit (also compared with normal saline). Whether specific populations and conditions benefit from dextrose prolotherapy (particularly compared with other non-surgical treatments) is an important area for future research, as some patients do not have sufficient improvement with other treatments for musculoskeletal pain. There are also concerns about side effects of some recommended treatments when used chronically (eg, corticosteroids) and some patients may have contraindications to certain pharmacologic options.

Injection therapies for musculoskeletal pain conditions are known to have large placebo effects that complicate rigorous evaluation of treatments.^137^ The natural history of most musculoskeletal pain conditions involves waxing and waning of symptoms, where patients seek medical attention during acute exacerbations of pain and pain-related disability, and then improve due to healing or homeostatic processes, lifestyle adjustments, and/or medical treatments.^138^ In a large well-designed RCT, the rates and average timing of improvements resulting from factors other than the treatment under study are expected to be balanced between intervention and comparator groups (including placebo when appropriate). However, small randomized trials may not adequately achieve balance across arms on these non-intervention effects and on other sources of confounding. Small trials are also more vulnerable to biases arising from attrition, particularly when the extent of attrition differs between groups. Furthermore, it may be challenging to maintain masking for injection interventions throughout a study, particularly when the these involve multiple different injections in and around an anatomic structure.^139^ These factors likely contributed to the low and very low COE for many findings in this report, and could be addressed by larger trials with sufficient follow-up.

Inconsistency in study findings was also likely due to the wide variation in dextrose concentrations, treatment duration and number of sessions, and other differences in injection technique, even for interventions addressing the same condition. Some of this variation may be clinically reasonable and expected due to differences in location of maximal pain for the affected joint or area and patient tolerance of procedures involving the specific anatomic structures implicated. In addition, and as customary in the overall treatment of musculoskeletal pain, there was no standardization of cointerventions or treatment algorithms that specified which options would be tried in sequence or concurrently. It is also possible that some cointerventions (eg, home exercise therapy) may be synergistic or antagonistic with the effects of the primary interventions being examined. All of these factors added to the challenges in interpretation of study findings and should be more systematically addressed in future studies.

Only 2 included studies reported on treatment costs for health care systems, and none evaluated cost and burden for patients. These are important considerations for health care payors, facilities, and patients, particularly given the chronic nature of most musculoskeletal pain conditions. There are likely differences in costs and treatment burden between the wide variety of non-surgical treatment options and dextrose prolotherapy, which all involve somewhat different resource needs for health care facilities and clinician training, as well as demands on patient time and other potential access barriers. In terms of injection therapies, the number and frequency of treatment sessions, as well as any additional clinician education would be important factors for health care facility resource needs. Future studies of dextrose prolotherapy for musculoskeletal pain conditions should include quantitative and qualitative assessments of the costs and treatment burden for health care systems and patients.

Most included studies did not use clear and systematic methods to evaluate adverse events for dextrose prolotherapy and various comparators. This is an essential gap for future research to address because this information will inform clinician decision-making, promote shared decision-making with well-informed patients, and potentially impact prioritization of limited medical resources. Trials should assess adverse events for each treatment arm using open-ended questions and/or checklists administered to all participants on a regular basis. Additionally, studies should clearly define the severity of adverse events (eg, serious events can be defined as life threatening, requiring hospitalization, or resulting in persistent disability) and rates of events that led to discontinuation of the treatment. Evaluation of adverse events will also require larger studies that are adequately powered to detect differences in adverse event rates across groups, and these studies will be necessary for each musculoskeletal pain condition because there is a strong possibility that harms could differ across conditions (and different injection locations).

In summary, future studies of prolotherapy should be of sufficient size and methodological quality to systematically assess efficacy and safety relative to currently recommended conservative treatments, as well as appropriate placebo controls given the likelihood of placebo effects associated with injection therapies. More work is also needed to evaluate treatment costs and burden.

## IMPLICATIONS FOR POLICY AND PRACTICE

Regarding efficacy, dextrose prolotherapy appeared to have differential effects across musculoskeletal pain conditions. Intra-articular dextrose prolotherapy probably had little to no benefit in pain-related functioning or physical performance for knee osteoarthritis, compared with normal saline injections. But evidence suggested benefits for plantar fasciitis and lateral elbow tendinopathy, compared with normal saline. In contrast, dextrose prolotherapy probably led to worse physical performance outcomes for shoulder pain, compared with corticosteroid injections. Therefore, these observations should be explored more thoroughly in well-designed and rigorous clinical trials that compare dextrose prolotherapy with other common conservative interventions for these pain conditions. The VA may be uniquely qualified and capable of undertaking these clinical investigations, as pharmaceutical companies are less likely to make the research investments needed to demonstrate the safety and efficacy of an inexpensive, non-proprietary, and easily accessible medication.

Generally, our report findings indicate that the evidence is very uncertain for adverse effects of dextrose prolotherapy, and more research is needed to establish the safety for clinical use of these procedures. Most studies on dextrose prolotherapy were small (N < 100) and many did not systematically evaluate or report adverse events. Even for treatments that were tested in larger clinical trials (with hundreds to thousands of participants), it is fairly common to find additional rare but serious side effects during more widespread use. An example of this is the reports of aseptic arthritis found in certain patients after repeat injections of hyaluronic acid.^140^

## CONCLUSIONS

Intra-articular dextrose prolotherapy probably had little to no benefit for pain-related functioning or physical performance in knee osteoarthritis, compared with normal saline injections. For shoulder pain due to mixed bursitis and rotator cuff pathology, dextrose prolotherapy probably resulted in worse physical performance outcomes, compared with corticosteroid injections. However, dextrose prolotherapy may improve pain-related functioning for lateral elbow tendinopathy and plantar fasciitis, compared with normal saline injection. Evidence on adverse events was generally lacking and severely limited by methodological concerns. The evidence was also very uncertain on the benefits of prolotherapy compared with other treatments or for other pain conditions. Given the lack of efficacious therapies for musculoskeletal pain conditions and interest in potential benefits of dextrose prolotherapy, future high-quality RCTs are needed to better understand the benefits and harms for this treatment.