# METHODS

## TOPIC DEVELOPMENT

The Integrated Project Team (IPT) on joint injectables for musculoskeletal pain was led by representatives from VA PMOP and Physical Medicine and Rehabilitation, and consisted of clinicians with subject matter expertise in pain treatments, including dextrose prolotherapy. This IPT served as the technical expert panel for this review. Collaboratively with the IPT, we defined the scope, formulated key questions, and determined eligibility criteria. We included a wide variety of dextrose prolotherapy interventions (concentrations, locations, and including other additives) that may be used to treat various musculoskeletal pain conditions.

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42024531179 (https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42024531179)). A draft version of this report was reviewed by the IPT; their comments and author responses are located in Appendix D.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions (KQs) were the focus of this review:

KQ 1 | What are the benefits and harms of dextrose prolotherapy for acute and chronic musculoskeletal pain?
KQ 2 | Do benefits and harms of dextrose prolotherapy vary by:; - Patient characteristics,; - Pain condition characteristics,; - Treatment history,; - Treatment parameters (eg, concentration, number of injections, use of imaging, setting of treatment)
KQ 3 | What are the costs of dextrose prolotherapy for health care systems and patients?

Study eligibility criteria are shown in the table below:

| Inclusion Criteria | Exclusion Criteria
Population | Adults (≥18 years) with acute or chronic musculoskeletal pain | <18 years old
Intervention | Dextrose prolotherapy (hypertonic, >5%) | Perineural 5% dextrose or nerve hydrodissection; spinal anesthesia (eg, for surgical procedures); nerve blocks
Comparator | Any | —
Outcomes | - Pain-related functioning or interference; - Physical performance (eg, range of motion, timed up and go); - Health-related quality of life; - Adverse events; - Pain severity or intensity; - Costs, resource use, access to care; - Treatment burden (patients and caregivers) | —
Timing | Any | —
Setting | Outpatient | Acute (hospital or emergency room)
Study Design | - RCTs; - Observational studies with ≥1 concurrent comparator group(s); - Cohorts with N ≥ 100, if reporting adverse events | Systematic reviews, study protocols, case reports, letters, conference abstracts, editorials, non-English studies (of any type), pre-clinical studies (in vitro or animal studies)

Abbreviations. RCT=randomized controlled trial.

## SEARCHING AND SCREENING

We searched MEDLINE, Embase, and Scopus databases from inception to February 2024, using key words and subject headings for dextrose prolotherapy for musculoskeletal conditions (eg, prolotherapy, regenerative injection, dextrose or glucose injection for joint or back conditions; see Appendix A for complete search strategies). Additional citations were identified from consultation with content experts. We also searched clinicaltrials.gov for recently completed and ongoing trials. For completed trials, we looked for publications associated with these trials using the protocol title, investigator names, and locations. Ongoing and completed trials without identified publications are noted in Appendix B.

Duplicate search results were removed, and abstracts were screened using DistillerSR version 2.35.^20^ Exclusion of abstracts required agreement of 2 reviewers. Included abstracts underwent full-text review by 2 individuals, with eligibility decisions requiring consensus of both reviewers.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Data abstraction was completed by 1 reviewer and verified by a second reviewer. Abstracted data included participant characteristics and inclusion/exclusion criteria, intervention characteristics (eg, content and location of injections, content of exercise programs, frequency, duration), study design and settings, and findings for eligible outcomes, as noted above. If findings were only reported in figures, we used PlotDigitizer (https://plotdigitizer.com/app) to extract data from figures, per recommended practices.^21^

Risk of bias (RoB) assessments were conducted independently by 2 researchers, and discrepancies were resolved by consensus or with a third reviewer. RCTs were assessed with Cochrane Risk of Bias 2.0^22^ and comparative cohort studies with the Cochrane Risk Of Bias In Non-randomised Studies - of Interventions (ROBINS-I).^23^ The 1 pre-post observational study was evaluated using the Joanna Briggs Institute Critical Appraisal Tool for Cohort Studies.^24^ RoB ratings per domain and overall are provided for each eligible study in Appendix E.

## SYNTHESIS

We first grouped studies by pain condition (eg, knee osteoarthritis, shoulder pain, plantar fasciitis) and then by intervention and comparator characteristics. For efficacy outcomes, we focused on between-group comparisons of the mean scores at follow-up time points, which we used to calculate bias-adjusted standardized mean differences (SMDs; Hedges’ g). When evaluating whether individual studies reported meaningful differences between groups, we compared the study findings against the minimal clinically important difference (MCID) whenever we were able to locate a suitable published reference for MCID. We required that the MCID reference evaluated a similar participant population (who were undergoing non-surgical treatments) and conducted rigorous determinations using anchor-based methods (eg, assessed specificity and sensitivity of MCID thresholds). For effect measures without published MCID references, we used statistical significance as reported by the included studies to determine if there were any differences. Description of outcome measures used by included studies, as well as MCID (if available) is provided in Table 1.

Table 1 Outcome Measures Reported by Included Studies

Outcome Category | Measure Name | Minimal Clinically Important Difference (MCID) | Scoring Range # of Items and Domains
Knee Osteoarthritis and Other Knee Pain
Pain-related functioning | WOMAC (Western Ontario and McMaster Universities Osteoarthritis Index) | Total: 12.5 (Salehi, 2023)^25^; Stiffness: 4.76 (Angst, 2018)^26^; Function: 11.25 (Angst, 2018)^26^ | 0-96 (lower is better); 24 items (3 domains)
Pain-related functioning | OKS (Oxford Knee Score) | 6.1 (Martín-Fernández, 2017)^27^ | 0-48 (higher is better); 12 items
Pain-related functioning | KOOS (Knee injury and Osteoarthritis Outcome Score) | ADL: 2.5 (Mills, 2016)^28^; QoL: 6.5 (Mills, 2016)^28^ | Scored by domain:; ADL 0-100 (higher is better), 17 items; QoL 0-100 (higher is better), 4 items
Pain-related functioning | VISA-P (Victorian Institute of Sport AssessmentPatella) | 13 (Hernandez-Sanchez, 2014)^29^ | 0-100 (higher is better); 8 items
Physical performance | TUG (Timed Up and Go) | No MCID | Normal range varies by age (<10 s for age <80 years old)
Physical performance | Isometric strength | No MCID | Variable
Physical performance | ROM (Range of Motion) | No MCID | Variable
Health-related quality of life | EuroQol 5D-3L (European Quality of Life – 5 Dimensions) | No MCID | 0-1 (higher is better)
Pain severity or intensity | WOMAC Pain | Pain: 7.09 (Angst, 2018)^26^ | Pain 0-20 (lower is better); 5 items
Pain severity or intensity | NRS (Numerical Rating Scale) | 1.0 (Salaffi, 2004)^30^ | 0-10 (lower is better)
Pain severity or intensity | VAS (Visual Analog Scale) | No MCID | 0-10 (lower is better)
Plantar Fasciitis and Other Foot Pain
Pain-related functioning | AOS (Ankle Osteoarthritis Scale) | No MCID | 0-100 (lower is better)
Pain-related functioning | FAAM (Foot and Ankle Ability Measure) | ADL: 8 (Martin, 2005)^31^; Sports: 9 (Martin, 2005)^31^ | Only scored by domain:; ADL 0-84 (higher is better), 29 items; Sports 0-32 (higher is better), 8 items
Pain-related functioning | FAOS (Foot and Ankle Outcome Score) | No MCID | 0-100 (higher is better)
Pain-related functioning | FFI (Foot Function Index) | No MCID | 0-100 (lower is better)
Pain-related functioning | MOXFQ (Manchester-Oxford Foot Questionnaire) | No MCID | 0-80 (lower is better); 16 items (3 domains)
Health-related quality of life | SF-36 Physical & Mental Component Scores | No MCID | 0-100 (higher is better)
Pain severity or intensity | NRS | 1.0 (Salaffi, 2004)^30^ | 0-10 (lower is better)
Pain severity or intensity | VAS | No MCID | 0-10 (lower is better)
Shoulder and Elbow Pain
Pain-related functioning | ASES (American Shoulder and Elbow Surgeons Score) | No MCID | 0-100 (higher is better); 13 items (2 domains)
Pain-related functioning | DASH (Disabilities of the Arm, Shoulder, and Hand Questionnaire) | 10.83 (Franchignoni, 2014)^32^ | 0-100 (lower is better); 30 items
Pain-related functioning | Quick DASH | 15.91 (Franchignoni, 2014)^32^ | 0-100 (lower is better); 11 items
Pain-related functioning | SPADI (Shoulder Pain and Disability Index) | 8.0 (Paul, 2004)^33^ | 0-130 (lower is better); 13 items (2 domains)
Pain-related functioning | WORC (Western Ontario Rotator Cuff Index) | No MCID | 0-2100 (lower is better); 21 items (5 domains)
Pain-related functioning | PRTEE (Patient-rated Tennis Elbow Evaluation) | 7 (Poltawski, 2011)^34^ | 0-100 (lower is better); 15 items (2 domains)
Physical performance | ROM | No MCID | Variable normal range
Physical performance | Grip strength | No MCID | Variable normal range
Health-related quality of life | EuroQol 5D-3L (European Quality of Life – 5 Dimensions) | No MCID | 0-1 (higher is better)
Pain severity or intensity | NRS | 1.0 (Salaffi, 2004)^30^ | 0-10 (lower is better)
Pain severity or intensity | VAS | No MCID | 0-10 (lower is better)
Chronic Low Back Pain
Pain-related functioning | ODI (Oswestry Disability Index) | 9.5 (Monticone, 2012)^35^ | 0-100 (lower is better); 10 items
Pain-related functioning | RMDQ (Roland-Morris Disability Index) | 2.5 (Monticone, 2012)^35^ | 0-24 (lower is better); 24 items
Pain-related functioning | DPQ (Dallas Pain Questionnaire) | No MCID | Scored by domain:; ADL 0-100 (lower is better) 7 items; Work/Leisure 0-100 (lower is better) 3 items
Health-related quality of life | SF-12 Physical & Mental Component Scores | Physical: 3.29 (Díaz-Arribas, 2017)^36^; Mental: 3.77 (Díaz-Arribas, 2017)^36^ | 0-100 (higher is better)
| Isometric strength | No MCID | Variable normal range
Physical Performance | ROM | No MCID | Variable normal range
Pain severity or intensity | NRS | 2.4 (van der Roer, 2006)^37^ | 0-10 (lower is better)
Pain severity or intensity | VAS | No MCID | 0-10 or 0-100 (lower is better)
Temporomandibular Joint Dysfunction and Pain
Pain-related functioning | NRS-Dysfunction (Numerical Rating Scale-Dysfunction) | No MCID | 0-10 (lower is better)
Physical performance | MMO (maximum mouth opening) | No MCID | 35-55 mm
Pain severity or intensity | NRS | No MCID | 0-10 (lower is better)
Pain severity or intensity | VAS | No MCID | 0-10 (lower is better)
Other Pain Conditions
Pain-related functioning | PRWE (Patient Rated Wrist Evaluation) | No MCID | 0-100 (lower is better)
Pain-related functioning | HAQDI (Health Assessment Questionnaire Disability Index) | No MCID | 0-3 (lower is better)
Pain-related functioning | DHI (Duruoz Hand Index) | No MCID | 0-90 (lower is better); 18 items
Pain-related functioning | FIQR (Fibromyalgia Impact Questionnaire, Revised) | No MCID | 0-100 (lower is better); 21 items (3 domains)
Pain-related functioning | VISA-A (Victorian Institute of Sport AssessmentAchilles) | No MCID | 0-100 (higher is better); 9 items (3 domains)
Physical performance | Grip strength | No MCID | Variable normal range
Physical performance | ROM | No MCID | Variable normal range
Physical performance | Lateral pinch strength | No MCID | Variable normal range
Pain severity or intensity | VAS | No MCID | 0-10 or 0-100 (lower is better)

Abbreviations. ADL=activities of daily living; MCID=minimal clinically important difference; QoL=quality of life.

We conducted meta-analyses when there were ≥3 studies for a given pain condition that evaluated sufficiently similar interventions and comparators, and reported the same outcome (eg, comparable measures of pain-related functioning or interference). Otherwise, we provided narrative syntheses of study characteristics and findings. For meta-analyses, we used random-effects models (with Hartung–Knapp-Sidik–Jonkman estimator) due to the anticipated heterogeneity in effects arising from variation in patient populations, clinical settings, and other study characteristics.

We assessed statistical heterogeneity using visual inspection of forest plots, τ^2^, and 95% prediction intervals (PIs). PIs describe the likeliest range of true effects (eg, true differences in pain-related functioning between study groups) across studies and provide an estimate of the magnitude and direction of associations that would be found in future studies similar to those included in a synthesis. PIs encompassing values similar to the overall estimate suggest limited heterogeneity, whereas PIs that include estimates in the same direction as the overall estimate but that vary widely in magnitude (eg, small to large positive SMDs) suggest moderate heterogeneity. If the PI encompasses estimates that range widely in both magnitude and direction, then substantial heterogeneity is likely present. We planned to assess publication bias using funnel plots if there were ≥10 sufficiently similar studies (according to considerations described above). We used meta and metafor packages and R version 4.3.1 to conduct meta-analyses and generate forest plots.^38^

### Certainty of Evidence

We prioritized 4 outcomes for certainty of evidence (COE) assessments, with input from IPT members. Before analysis and synthesis of eligible study findings, we met with the IPT to discuss prioritization of outcomes for COE assessments and, after the meeting, conducted an online survey requesting ranking of the outcomes into the top 3 for importance (ie, indicate which outcome is first, second, or third, from among the eligible outcomes). The top 3 prioritized outcomes were pain-related functioning or interference, physical performance, and quality of life. As evidence on adverse events is necessary for weighing the balance of risks and benefits, we also rated COE for adverse events. We assessed COE separately for dextrose prolotherapy compared with different treatments (eg, corticosteroid injections or exercise), when there were at least 2 studies evaluating the same comparison. Additionally, we separately assessed COE for outcomes at short-term (3-6 weeks), medium-term (3-4 months), and long-term (≥6 months) follow-up. We took into consideration that dextrose prolotherapy is often initially painful over first 1-2 weeks (thought due to activation of inflammatory pathways) and then potentially improves healing thereafter, which would take additional weeks. Furthermore, comparator injections (eg, corticosteroids) are often evaluated for clinical efficacy over a period of several months. Thus, we set the short-term interval at a time when we could reasonably expect any improvement with prolotherapy, and then the medium timeframe comparable to other treatments in terms of a reasonable duration of effect. Lastly, we determined that efficacy at 6 months or longer would be an important potential difference from improvements that only lasted 3-4 months.

We used Grading of Recommendations, Assessment, Development, and Evaluation (GRADE) methodology to rate overall COE as high, moderate, low, or very low (Table 2).^39,40^ Briefly, for each prioritized outcome, we used GRADEpro Guideline Development Tool (GDT)^40^ to systematically evaluate 5 domains: study limitations (risk of bias), imprecision (limitations in precision of effect estimates), inconsistency (in direction and magnitude of effects across studies), indirectness (applicability of the results), and other considerations (including publication bias). For imprecision, we also considered the optimal information size (OIS),^41^ but used a different approach for efficacy outcomes and adverse events because the former were continuous measures while the latter were usually reported as counts (or participants). For efficacy outcomes, we determined the sample size needed (for 2-tailed α = 0.05 and β = 0.2) to detect either: 1) the MCID (when available) converted to SMD using reported standard deviations (SD), or 2) an SMD of 0.7-0.8 (when there was no established MCID). In these latter cases, we elected to use SMD (for ~large effect size) because our experience with calculating SMD derived from available MCID was that these generally gave SMD in this range or higher. Additionally, in studies where authors described sample size calculations, the targeted SMD was always large (or very large) effect sizes. For adverse events, we applied OIS by considering the minimum detectable event rate using the sample size of the dextrose prolotherapy arm. We downgraded 2 levels if the minimum detectable rate was ≥ 20%, and 1 level if this was ≥ 10%.

Table 2 GRADE Certainty of Evidence Ratings: Definitions and Recommended Statements^39,40^

Certainty of Evidence | Rating Definition | Recommended Statements (“What Happens”)
High | We are very confident that the true effect lies close to that of the estimate of the effect. | Intervention reduces/increases/improves outcome.; Intervention results in little to no difference in outcome.
Moderate | We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different. | Intervention probably reduces/increases/improves outcome.; Intervention probably results in little to no difference in outcome.
Low | Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect. | Intervention may reduce/increase/improve outcome.; Intervention may result in little to no difference in outcome.
Very Low | We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect. | The evidence is very uncertain about the effect of intervention on outcome.