# BACKGROUND

Musculoskeletal diseases are the most common reason for chronic pain among adults in the US.^1^ Osteoarthritis is the most common musculoskeletal disease globally, impacting nearly 8% of the world’s population (595 million individuals).^2^ Osteoarthritis is a degenerative condition that generally affects older adults and is a leading cause of pain and disability in this population.^3–7^ Rates of osteoarthritis are increasing in the US due to an aging population and the increased prevalence of obesity.^8^ The knee is the most commonly afflicted joint, affecting an estimated 14 million US adults,^9^ and knee osteoarthritis is also responsible for the largest proportion of economic costs and disability related to osteoarthritis.^10,11^ Beyond osteoarthritis, other joint and peri-articular conditions are also common and have substantial associated morbidity. For example, shoulder pain due to various etiologies accounts for 16% of musculoskeletal complaints in US primary care patients,^12^ and heel pain from plantar fasciitis has a lifetime incidence of 10% among US adults.^13^

Musculoskeletal pain conditions are often challenging for patients and clinicians, which in turn drives demand and utilization of health care services. The breadth of available treatments includes non-pharmacological interventions (eg, physical therapy), topical and oral systemic pharmacologic therapies, localized injection therapies, and surgical procedures. Most of these treatments address symptoms such as pain and joint instability, but do not alter disease progression. Furthermore, disease severity based on imaging findings (eg, for knee osteoarthritis) often does not correspond with patient-reported symptoms (eg, pain and functioning), adding to the complexity of clinical management.^14^ For patients who have insufficient symptom improvement from non-pharmacologic, and topical and/or systemic pharmacologic treatments, targeted injection therapies are often offered before more invasive surgical procedures. Additionally, surgery may not be the best option for certain patients due to a variety of factors, such as the expected improvement versus risks from surgery and patient preferences.^15–17^

Prolotherapy involves injecting an irritant solution into an affected joint and/or connective tissues to improve musculoskeletal pain and function.^18^ The true physiologic effects are not well understood but the putative mechanism involves eliciting a low-grade inflammatory response that stimulates the natural healing process of connective tissue and potentially alters pain perception pathways. Hypertonic dextrose is the most commonly utilized type of prolotherapy solution, and its use was first reported by Hackett et al. nearly 70 years ago.^19^ Current prolotherapy solutions differ both in the concentration of dextrose and the inclusion of other chemicals. Moreover, dextrose prolotherapy interventions vary in the number and duration of injection treatments, the anatomic locations, injection techniques, and use of imaging guidance, even for interventions used to treat the same musculoskeletal pain condition.

In fiscal year 2023, a total of 1,454 dextrose prolotherapy injection procedures were administered in VA health care facilities, and there were 59 VA Care in the Community claims totaling $20,839. Dextrose prolotherapy is also commonly used in practice outside of VA care, but the total costs and utilization in non-VA settings are difficult to ascertain as these procedures are not covered by major health insurers and there is no corresponding Current Procedural Terminology (CPT) code for it.

VA Pain Management, Opioid Safety and Prescription Drug Monitoring Program (PMOP) and Physical Medicine and Rehabilitation Services (PM&RS) are coleading the development of VA practice recommendations on injection therapies for musculoskeletal pain conditions and requested this systematic review to support those effort and help guide future research. This review synthesizes evidence on the benefits and harms of dextrose prolotherapy for a range of musculoskeletal pain conditions, including knee osteoarthritis, plantar fasciitis, shoulder pain, lateral elbow tendinopathy, chronic low back pain, and pain due to temporomandibular joint dysfunction.