# APPENDIX L OTHER PAIN CONDITIONS

Appendix Table 16 Detailed Study Characteristics for All Eligible Studies on Other Pain Conditions

Appendix Table 17 Detailed Results for All Eligible Studies on Other Pain Conditions