# APPENDIX K TEMPOROMANDIBULAR JOINT (TMJ) DISORDERS

Appendix Table 14 Detailed Study Characteristics for All Eligible TMJ Studies

Appendix Table 15 Detailed Results for All Eligible TMJ Studies