# APPENDIX J CHRONIC LOW BACK PAIN (LBP)

Appendix Table 12 Detailed Study Characteristics for All Eligible Chronic Low Back Pain (LBP) Studies

Appendix Table 13 Detailed Results for All Eligible Chronic Low Back Pain Studies