# APPENDIX I LATERAL ELBOW TENDINOPATHY

Appendix Table 10 Detailed Study Characteristics for All Eligible Elbow Pain Studies

Appendix Table 11 Detailed Results for All Eligible Elbow Pain Studies