# APPENDIX H SHOULDER PAIN

Appendix Table 8 Detailed Study Characteristics for All Eligible Shoulder Pain Studies

Appendix Table 9 Detailed Results for All Eligible Shoulder Pain Studies