# APPENDIX G PLANTAR FASCIITIS

Appendix Table 6 Detailed Study Characteristics for All Eligible Plantar Fasciitis Studies

Appendix Table 7 Detailed Results for All Eligible Plantar Fasciitis Studies