# APPENDIX F KNEE OSTEOARTHRITIS

Appendix Table 3 Detailed Study Characteristics for All Eligible Knee OA Studies

Appendix Table 4 Detailed Results for Eligible Knee Osteoarthritis Studies: Intra-Articular and Extra-Articular Dextrose Injections

Appendix Table 5 Detailed Results for Eligible Knee Osteoarthritis Studies: Intra-Articular or Extra-Articular Dextrose Injections