# APPENDIX E RISK OF BIAS ASSESSMENTS

Appendix Table 1 Risk of Bias Ratings for All Eligible Randomized Controlled Trials (ROB-2)

Trial Name or Author Year | Bias from Randomization Process | Bias from Deviation from Intended Interventions (Assignment) | Bias from Deviation from Intended Interventions (Adherence) | Bias from Missing Outcome Data | Bias in Measurement Of Outcome | Bias in Selection Of Reported Result | Overall Risk Of Bias; (Low, Some Concerns, High)
Abd Karim, 2023^78^ | Low | Low | Low | High | Low | Low | High
Ahadi, 2019^89^ | Some concerns | Low | High | Low | Some concerns | Some concerns | High
Akcay, 2020^88^ | Low | High | Low | Some concerns | Low | Some concerns | High
Apaydin, 2020^96^ | Some concerns | Low | Some concerns | Low | Some concerns | Low | High
Arafat, 2019^116^ | Some concerns | Some concerns | Low | Some concerns | Some concerns | Some concerns | High
Asheghan, 2021^71^ | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns
Babaeian, 2022^50^ | Low | High | Low | Some concerns | Low | Low | High
Babaei-Ghazani, 2023^125^ | Low | Some concerns | Low | Low | Low | Low | Some concerns
Bayat, 2019^94^ | Some concerns | High | High | Low | Low | Low | High
Bayat, 2023^60^ | High | High | High | High | Low | Low | High
Baygutalp, 2021^58^ | Some concerns | Some concerns | High | Low | High | Some concerns | High
Bertrand, 2016^85^ | Some concerns | High | Low | Some concerns | Low | Low | High
Bhargava, 2023^117^ | Some concerns | High | High | High | Some concerns | Some concerns | High
Chang, 2021^75^ | Some concerns | Low | Low | Low | Low | Low | Some concerns
Chhapane, 2023^118^ | Some concerns | Low | Some concerns | Some concerns | Some concerns | Low | High
Ciftci, 2023^93^ | Low | Some concerns | Low | Low | Low | Low | Some concerns
Cole, 2018^84^ | Some concerns | Low | Some concerns | Some concerns | Low | Some concerns | High
Comert, 2016^119^ | Some concerns | Some concerns | Low | Some concerns | Some concerns | Some concerns | High
Deb, 2020^92^ | Some concerns | High | High | High | Some concerns | Some concerns | High
Dechow, 1999^100^ | Some concerns | Some concerns | High | Low | Low | Some concerns | High
Dumais, 2012^61^ | Low | High | High | High | Low | Low | High
Ersen, 2018^66^ | Low | Low | High | Some concerns | High | Some concerns | High
Eua, 2018^69^ | Low | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns
Farpour, 2017^49^ | Low | Low | Some concerns | Low | Low | Low | Some concerns
Fouda, 2018^109^ | Some concerns | Low | High | High | Low | Some concerns | High
George, 2018^77^ | Some concerns | Low | High | Low | Some concerns | Some concerns | High
Gul, 2020^130^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Some concerns | Some concerns
Gupta, 2022^97^ | High | Low | Low | Low | Some concerns | Some concerns | High
Hadianfard, 2023^126^ | Low | Low | Low | Low | Low | Some concerns | Some concerns
Haggag, 2022^110^ | Some concerns | High | Low | High | Low | Some concerns | High
Hashemi, 2015^51^ | Some concerns | High | Some concerns | Low | Some concerns | Some concerns | High
Hassanien, 2020^111^ | Some concerns | Some concerns | Low | Some concerns | Some concerns | Some concerns | High
Hooper, 2011^136^ | Low | High | Low | Some concerns | Low | Some concerns | High
Hosseini, 2019^54^ | Low | High | High | Low | Some concerns | Low | High
Hsieh, 2022^43^ | Low | Low | Low | Low | Low | Low | Low
Jahangiri, 2016^127^ | Low | Low | Low | Some concerns | Low | Low | Some concerns
Karakilic, 2023^65^ | Some concerns | Low | High | High | Some concerns | Some concerns | High
Kaya, 2022^95^ | Low | High | High | High | Some concerns | Some concerns | High
Kazempour Mofrad, 2021^81^ | High | Low | Low | Low | Some concerns | Low | High
Kesikburun, 2022^67^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | High
Kim, 2010^107^ | Low | Some concerns | Low | Low | Low | Some concerns | Some concerns
Kim, 2014^72^ | High | Some concerns | Low | Low | Low | Some concerns | High
Klein, 1993^101^ | Some concerns | Some concerns | Some concerns | Low | Low | Some concerns | High
Lin, 2022^74^; Lin, 2019^76^ | Low | Low | Low | Low | Low | Low | Low
Lin, 2023^73^ | Low | Low | Some concerns | Low | Low | Low | Some concerns
Louw, 2019^112^ | Low | Low | Low | Some concerns | Low | Low | Some concerns
Mahmoud, 2018^113^ | Some concerns | Some concerns | High | Some concerns | Some concerns | Some concerns | High
Mansiz-Kaplan, 2020^68^ | Low | Some concerns | Low | Some concerns | Low | Low | Some concerns
Mruthyunjaya, 2023^46^ | Low | High | Low | High | Some concerns | Low | High
Mustafa, 2018^120^ | Some concerns | High | Low | Low | Some concerns | Some concerns | High
Nasiri, 2021^80^ | Some concerns | Some concerns | High | Some concerns | Low | Low | High
Ongley, 1987^102^ | Some concerns | Some concerns | Low | Low | Low | Some concerns | Some concerns
Ozturk, 2023^56^ | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns
Pishgahi, 2020^47^ | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns
Priyadarshini, 2021^114^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Some concerns | High
Rabago, 2013a^63^ | Low | Low | Low | Some concerns | Low | Low | Some concerns
Rabago, 2013b^90^ | Some concerns | Low | Some concerns | Some concerns | High | Some concerns | High
Rahimzadeh, 2018^48^ | Low | Some concerns | Low | Low | Low | Low | Some concerns
Raissi, 2022^106^ | Low | Some concerns | Low | Low | Low | Low | Some concerns
Raissi, 2023^70^ | Some concerns | Low | Some concerns | Some concerns | Low | Low | Some concerns
Reeves, 2000^44^ | Low | High | Low | High | Low | Some concerns | High
Refai, 2011^122^ | High | High | Low | Some concerns | Low | Some concerns | High
Rezasoltani, 2017^42^ | Low | Low | Some concerns | High | Low | Low | High
Rezasoltani, 2020^53^ | Some concerns | Some concerns | High | Low | High | High | High
Saadat, 2018^123^ | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns | High
Sam, 2023^79^ | Low | High | Low | Some concerns | Low | High | High
Sari, 2020^82^ | Some concerns | Some concerns | Low | Low | Low | Some concerns | High
Scarpone, 2008^91^ | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Sert, 2020^59^ | Low | High | High | Low | High | Low | High
Seven, 2017^83^ | Some concerns | High | High | High | Some concerns | Some concerns | High
Sit, 2020^45^ | Low | Low | Low | Low | Low | Low | Low
Ustun, 2023^132^ | High | Some concerns | High | Low | Some concerns | Low | High
Waluyo, 2021^64^ | Some concerns | High | High | High | Low | Low | High
Wu, 2022^135^ | Low | Low | Low | High | Low | Some concerns | High
Yelland, 2004^99^ | Low | Low | Some concerns | High | Low | Low | High
Yelland, 2011^129^ | Low | Low | Low | Low | Some concerns | Low | Some concerns
Yelland, 2019^98^ | Low | Low | High | Some concerns | Some concerns | High | High
Yildiz, 2023^62^ | Some concerns | Low | Low | Low | High | Low | High
Zarate, 2020^115^ | Low | Low | Low | Low | Low | Low | Low

Appendix Table 2 Risk of Bias Ratings for All Eligible Nonrandomized Comparison Studies (ROBINS-I)

Study Name or Author Year | Bias Due To Confounding | Selection Bias | Bias in Classification of Interventions | Bias Due to Departures from Intended Interventions | Bias Due to Measurement of Outcomes | Bias Due to Missing Data | Bias in the Selection of Reported Results | Overall Risk of Bias (Low, Moderate, Serious, Critical, No Information)
Abd Elghany, 2019^133^ | Low (except for concerns about uncontrolled confounding) | Low | Low | Moderate | Low | Moderate | Low | Moderate
Akpancar, 2019^131^ | Low (except for concerns about uncontrolled confounding) | Low | Moderate | Critical | Serious | Moderate | Low | Critical
Cho, 2017^128^ | Low (except for concerns about uncontrolled confounding) | Low | Low | Moderate | Serious | Moderate | Low | Serious
Derby, 2004^104^ | Low (except for concerns about uncontrolled confounding) | Low | Low | Moderate | Serious | Serious | Moderate | Serious
Elwerfelli, 2019^108^ | Serious | Low | Low | Low | Serious | Moderate | Low | Serious
Jacks, 2012^103^ | Low (except for concerns about uncontrolled confounding) | Low | Low | Low | Low | Low | Low | Low
Pandey, 2022^121^ | Low (except for concerns about uncontrolled confounding) | Low | Low | Moderate | Serious | Moderate | Moderate | Serious
Senturk, 2017^134^ | Low (except for concerns about uncontrolled confounding) | Low | Low | Moderate | Serious | Serious | Low | Serious
Soliman, 2016^57^ | Low (except for concerns about uncontrolled confounding) | Low | Low | Moderate | Serious | Serious | Low | Serious
Yildirim, 2021^105^ | Low (except for concerns about uncontrolled confounding) | Low | Low | Low | Low | Moderate | Low | Moderate