# APPENDIX D PEER REVIEW COMMENTS AND RESPONSES

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you for your comment.
2 | 3 | Yes | Thank you for your comment.
3 | 5 | Yes | Thank you for your comment.
4 | 6 | Yes | Thank you for your comment.
Is there any indication of bias in our synthesis of the evidence?
5 | 1 | No | Thank you for your comment.
6 | 3 | No | Thank you for your comment.
7 | 5 | No | Thank you for your comment.
8 | 6 | Yes - Overall I feel the information presented skews prolotherapy in a negative light. Even when some semblances of positive outcomes are noted in a study, the next line if followed by a negative comment.; There are many phrases that include ‘probably” which seems to imply that the data was looked at and although there was benefit, it probably wasn’t meaningful to the author. | Our goal is to provide a balanced and accurate synthesis of the existing evidence on benefits and harms of dextrose prolotherapy. We sought to report completely the findings from relevant published evidence on this treatment. In the conduct of this review, we followed recommended protocols for identifying, assessing, and synthesizing the evidence on dextrose prolotherapy. We involved an expert advisory panel and stakeholders in developing the review protocol, which was established a priori before we finalized selection of eligible studies and analysis of study findings. We also engaged the advisory panel in deciding how to categorize and synthesize the evidence, before any analysis of findings.; As noted below in response to comment #21, we have provided more information about GRADE ratings for certainty of evidence, and the recommended language to reflect a specific rating (eg, “probably” is used for moderate certainty)
Are there any published or unpublished studies that we may have overlooked?
9 | 1 | No | Thank you for your comment.
10 | 3 | No | Thank you for your comment.
11 | 5 | No | Thank you for your comment.
12 | 6 | No | Thank you for your comment.
Additional suggestions or comments can be provided below.
13 | 1 | None. | Thank you for your comment.
14 | 3 | Thank you for your comment. | I found the report to be well written and balanced. The conclusions are supported by the Evidence that was found.
15 | 5 | PDF p. 12, line 4 – “eligibles”; PDF p. 12, line 31 – is “KQ” defined prior to this in the executive summary (it is defined in the main report)? | We have corrected this and spelled out “Key Question” for KQ.
16 | 5 | PDF p. 13, line 27 – comparators were normal saline, corticosteroid or PT/exercise programs, or were there 2 arms in the same study (e.g., normal saline in 1 arm and corticosteroid injection in another arm)? I wasn’t clear from this sentence. | We have clarified this sentence to indicate that these were mostly separate studies with these different comparators. There was one study that had 4 arms, comparing dextrose prolotherapy with normal saline, corticosteroid injection, and PRP (Table 15).
17 | 5 | PDF p. 14, lines 25-35 (KQ2) – the question asks about benefits and harms, but the text below mostly discusses (lack of) benefit, not harms (or even a statement here saying there was not enough evidence to comment on this, etc.). | We have clarified that lack of an impact on the 4 prioritized outcomes include both efficacy outcomes (pain-related functioning, physical performance, and health-related quality of life), and adverse events.
18 | 5 | PDF p. 15, line 5 – “benefits” should probably be “benefit”; PDF p. 15, line 14 – just FYI, an additional reason is that some patients are not surgical candidates (e.g., high risk because of comorbidities, do not wish to undergo surgery, don’t have sufficient support during rehabilitation from surgery, etc.). | We have corrected this.; We agree with reviewer’s point and had noted these same points in the Introduction (pg. viii): “…surgery may not be the best option for certain patients due to a variety of factors, such as the expected improvement vs. risks from surgery and patient preferences.”
19 | 5 | PDF p. 17, line 12 – RCTS should be RCTs? This occurs multiple times in the manuscript – find & replace. | We have corrected this.
20 | 5 | PDF p. 32, Figure 1 – it wasn’t clear to me how many studies were excluded because of low N – would this be under “ineligible study design or publication” or some other heading (e.g., ineligible population)? | The exclusion criteria related to study sample size (≥ 100) was only applied to non-comparative cohort studies, RCTs and comparative cohorts of any size were included (if they met the other eligibility criteria). We included non-comparative cohort studies in order to supplement the evidence on harms from RCTs and comparative cohort studies, which we anticipated may be limited. The number of non-comparative cohort studies with N <100 was not specifically tracked but included within the category “ineligible study design or publication type” (as the reviewer noted).
21 | 5 | General comments; - pain-related is sometimes hyphenated, sometimes not hyphenated throughout the text. Consider standardizing.; - GRADE Working Group grades of evidence – might be helpful to have this definition (e.g., PDF p. 61, lines 44-50) earlier in the manuscript, as this may be more unfamiliar to readers than “letter grades” or other grading systems?I | We have corrected this to be “pain-related functioning” throughout the report. Regarding GRADE ratings, we have now added the definition of these ratings to the Methods (in both the Executive Summary and the main report), along with the recommended language for describing these ratings.
22 | 6 | Page 12 Lines 37-38 “Probably” seems like a vague descriptor. | As noted above in response to comment #21, we have provided more information about the GRADE ratings and the recommended language for describing these ratings (eg, “probably” is used for moderate certainty).
23 | 6 | Serious side effects is mentioned but not described from my reading. This feels biased. | Please see our response below to comment #28.
24 | 6 | Page 12 Line 7 For shoulder what is the “Worse physical outcome when compared to steroid.”? | We are uncertain if reviewer is still referencing lines 37-38 on pg. xiii (in the original draft report), which states “In contrast, our findings indicated that for shoulder pain, dextrose prolotherapy probably led to worse physical performance outcomes, compared with corticosteroid injections.” If so, then the physical performance outcomes referred to in this sentence included range of motion for a variety of movements, such as forward flexion, abduction, etc. For studies addressing other pain conditions, other physical performance measures were used (eg, gait speed in studies of knee osteoarthritis). As this is a summary sentence in the Discussion, we did not list all the measures again. The exact physical performance measures are described in the main report (Tables 15 and 17, and text sections), We have also added clarifications to these outcomes in the Executive Summary results portion (pg. xii).
25 | 6 | Page 12 Lines 37-38 “probably has…” I don’t feel this is an appropriate word. It either did or did not. | As indicated in response to comment #21, we added more information about the GRADE ratings and the recommended language for describing these ratings (eg, “probably” is used for moderate certainty).
26 | 6 | In discussion of Prolotherapy costs, it is NOT pointed out that dextrose is cheap. And burden of care for patients is talked about as it if were implied to be high but no evidence suggests that. Also where is safety data? | Our Discussion focuses on the evidence gaps regarding treatment costs and burden because we only identified 2 studies that addressed costs and neither examined treatment burden from the perspective of patients and caregivers. We highlight the factors that generally contribute to costs and resource needs for in-clinic treatments, including staff training as needed to establish and maintain competence. Similarly, for treatment burden, we are also alluding generally to factors that would impact this for patients, such as various access barriers.; The findings on harms or safety are presented in the sections on KQ 1 and 2 in both the Executive Summary and the Main text. In general, the evidence on harms or safety was lacking, due to a variety of factors. The included studies generally did not systematically evaluate adverse events and varied greatly in what was reported. Additionally, most studies were very small, which meant they had limited power to detect side effects that were uncommon.
27 | 6 | Page 16 lines 33-34. Again, the line reads ‘Probably’ had little to no benefit. It either did or did not. This phrasing makes it sound like the study showed it had some effect but you don’t want to acknowledge it or you don’t feel like it was significant enough. Same in lines 38-39 | As noted above in response to comment #21, we added more information about the GRADE ratings and the recommended language for describing these ratings (eg, “probably” is used for moderate certainty).
28 | 6 | Page 16 Line 49. State more research it needed to establish the “safety” yet nothing has been described as being unsafe or harmful with the treatments. Lines 53-54. What is the common, rare, serious side effect you are trying to make readers believe if present? | Clinical decision-making (and guidelines) must weigh efficacy (improvement in outcomes) vs. harms (risks and side effects) for any given treatment; thus, evidence is needed to address both sides of this equation. The included studies generally did not systematically evaluate adverse events and varied greatly in what was reported. For example, some rates reported the rates (and extent) of post-injection pain and others made only general statements that no severe side effects were observed (but did not define what was considered to be severe). Therefore, even for something that appeared to be fairly common (eg, higher pain post-injection), there was insufficient evidence for pooled estimates of the risk. In the main report, we also provide a specific example of a serious but rare side effect that was observed only after more widespread use of viscosupplementation. Although not included in our report, there are also many other examples of infrequent, serious side effects that emerged (or were better understood) only with larger studies or greater population exposure. These include rates of deep venous thromboembolism with oral contraceptives (<1%/year) and liver failure with terbinafine (<<0.1%). Some of these infrequent side effects may be anticipated based on the mechanism of the treatment, but others were surprising and more idiosyncratic. Therefore, our main point here is to highlight the uncertainty regarding the evidence for safety of dextrose prolotherapy.
29 | 6 | Page 25, line 46-47. What about the safety record of PROLO? Something should mentioned here. | An important part of the goal of this systematic review was to identify and synthesize evidence on the harms of dextrose prolotherapy. As noted above in response to comments #26 and 28, studies had a variety of methodological limitations that led to very low certainty of evidence for harms across different pain conditions.