# APPENDIX C EXCLUDED STUDIES

Citation | | Exclude Reason
1. | Corrigendum to: Prolotherapy vs Radial Extracorporeal Shock Wave Therapy in the Short-term Treatment of Lateral Epicondylosis: A Randomized Clinical Trial. Pain medicine (Malden, Mass). 2019;20(12):2612. Erratum for: Pain Med. 2019 Sep 1;20(9):1745–1749 PMID: 30698771 [https://www.ncbi.nlm.nih.gov/pubmed/30698771]30698771 | Ineligible study design or publication type
2. | Allen Hooper R, Yelland M, Fonstad P, Southern D. Prospective case series of litigants and non-litigants with chronic spinal pain treated with dextrose prolotherapy. Article. Int Musculoskelet Med. 2011;33(1):15–20 | Ineligible study design or publication type
3. | Amanollahi A, Asheghan M, Hashemi SE. Subacromial corticosteroid injection versus subcutaneous 5% dextrose in patients with chronic rotator cuff tendinopathy: A short-term randomized clinical trial. Interventional medicine & applied science. 2020;11(3):154–160 36343292 | Ineligible intervention
4. | Babaei-Ghazani A, Moradnia S, Azar M, . Ultrasound-guided 5% dextrose prolotherapy versus corticosteroid injection in carpal tunnel syndrome: a randomized, controlled clinical trial. Pain management. 2022;12(6):687–697 35848821 | Ineligible intervention
5. | Berberet B, Burda A, Breier C, Lodolce AE. Discontinuation of 5% alcohol in 5% dextrose injection: implications for antidote stocking. American publication type journal of health-system pharmacy : AJHP : official journal of the American Society of Health-System Pharmacists. 2008;65(23):2200–2203 | Ineligible study design or publication type
6. | Carayannopoulos A, Borg-Stein J, Sokolof J, Meleger A, Rosenberg D. Prolotherapy versus corticosteroid injections for the treatment of lateral epicondylosis: a randomized controlled trial. PM & R : the journal of injury, function, and rehabilitation. 2011;3(8):706–15. Comment in: PM R. 2012 Apr;4(4):322–3; author reply 323 PMID: 22541380 [https://www.ncbi.nlm.nih.gov/pubmed/22541380]22541380 | Ineligible intervention
7. | Chen CPC, Suputtitada A. Prolotherapy at Multifidus Muscle versus Mechanical Needling and Sterile Water Injection in Lumbar Spinal Stenosis. Journal of pain research. 2023;16:2477–2486 37483410 | Ineligible intervention
8. | Chen JL, Chen CH, Cheng CH, Chen CC, Lin KY, Chen CPC. Can the addition of ultrasound-guided genicular nerve block using 5% dextrose water augment the effect of autologous platelet rich plasma in treating elderly patients with knee osteoarthritis? Article. Biomed J. 2021;44(6):S144–S153 35289285 | Ineligible intervention
9. | Comert Kilic S, Kilic N, Gungormus M. Botulinum Toxin Versus Dextrose Prolotherapy: Which is More Effective for Temporomandibular Joint Subluxation? A Randomized Clinical Trial. Journal of oral and maxillofacial surgery : official journal of the American Association of Oral and Maxillofacial Surgeons. 2023;81(4):389–395 36693543 | Ineligible outcome
10. | Covey CJ, Sineath MH, Jr P, Joseph F L. Prolotherapy: Can it help your patient? The Journal of family practice. 2015;64(12):763–8 26844994 | Ineligible study design or publication type
11. | Dean Reeves K, Fullerton BD, Topol G. Evidence-Based Regenerative Injection Therapy (Prolotherapy) in Sports Medicine. The Sports Medicine Resour Man. 2008:611–619 | Ineligible study design or publication type
12. | Ferouz F, Norris MC, Arkoosh VA, Leighton BL, Boxer LM, Corba RJ. Baricity, needle direction, and intrathecal sufentanil labor analgesia. Anesthesiology. 1997;86(3):592–8 9066324 | Ineligible population
13. | Furman MB, Reeves RS, Ante WA. Intradiscal Steroids and Prolotherapy: Clinical Relevance, Outcomes and Efficacy. Interventional Spine E-Book: An Algorithmic Approach. 2007:1049–1055 | Ineligible study design or publication type
14. | Hackett GS. Prolotherapy in whiplash and low back pain. Postgraduate medicine. 1960;27:214–9 13830709 | Ineligible study design or publication type
15. | Hackett GS, Huang TC, Raftery A. Prolotherapy for headache. Pain in the head and neck, and neuritis. Headache. 1962;2:20–8 13903423 | Ineligible study design or publication type
16. | Hackett GS, Huang TC, Raftery A, Dodd TJ. Back pain following trauma and disease-prolotherapy. Military medicine. 1961;126:517–25 13710286 | Ineligible study design or publication type
17. | Hashemi SM, Madadi F, Razavi S, Nikooseresht M, Kiyabi FH, Nasiripour S. Intra-articular hyaluronic acid injections Vs. dextrose prolotherapy in the treatment of osteoarthritic knee pain. Tehran University Medical Journal. 2012;70(2):119–125 | Not published in English
18. | Hauser R, Woldin B. Treating osteoarthritic joints using dextrose prolotherapy and direct bone marrow aspirate injection therapy. Open Arthritis Journal. 2014;7(1):1–9 | Ineligible intervention
19. | Hauser RA. Punishing the pain. Treating chronic pain with prolotherapy. Rehab management. 1999;12(2):26–30 10350899 | Ineligible study design or publication type
20. | Hauser RA, Blakemore PJ, Wang J, Steilen D. Structural basis of joint instability as cause for chronic musculoskeletal pain and its successful treatment with regenerative injection therapy (Prolotherapy). Open Pain Journal. 2014;7(1):9–22 | Ineligible study design or publication type
21. | Hoffman MD, Agnish V. Functional outcome from sacroiliac joint prolotherapy in patients with sacroiliac joint instability. Complementary therapies in medicine. 2018;37:64–68 29609940 | Ineligible study design or publication type
22. | Hu LP, Huang AB, Xu YL. Effective assessment of hip joint soft tissue release in lightening the ache symptom of ankylosing spondylitis. Chinese Journal of Clinical Rehabilitation. 2005;9(34):80–81 | Not published in English
23. | Hung C-Y, Chang K-V, Ozcakar L. Snapping Hip due to Gluteus Medius Tendinopathy: Ultrasound Imaging in the Diagnosis and Guidance for Prolotherapy. Pain medicine (Malden, Mass). 2015;16(10):2040–1 26119901 | Ineligible study design or publication type
24. | Imani F, Hejazian K, Kazemi M-R, Narimani-Zamanabadi M, Malik KM. Adding Ozone to Dextrose and Somatropin for Intra-articular Knee Prolotherapy: A Randomized Single-Blinded Controlled Trial. Anesthesiology and pain medicine. 2020;10(5):e110277 34150571 | Ineligible intervention
25. | Isik R, Karapolat H, Bayram KB, Usan H, Tanigor G, Atamaz Calis F. Effects of Short Wave Diathermy Added on Dextrose Prolotherapy Injections in Osteoarthritis of the Knee. Journal of alternative and complementary medicine (New York, NY). 2020;26(4):316–322 | Ineligible intervention
26. | Jacks A, Barling T. Lumbosacral prolotherapy. Letter. Int Musculoskelet Med. 2013;35(1):44 | Ineligible study design or publication type
27. | Kajbaf J. Prolotherapy. Regenerative MedicineL: A Complete Guide for Musculoskeletal and Spine Disorders. 2022:15–27 | Ineligible study design or publication type
28. | Katsinelos P, Kountouras J, Chatzimavroudis G, . A novel technique of injection treatment for endoscopic sphincterotomy-induced hemorrhage. Article. Endoscopy. 2007;39(7):631–636 17611918 | Ineligible population
29. | Kayfetz DO, Blumenthal LS, Hackett GS, Hemwall GA, Neff FE. Whiplash injury and other ligamentous headache-its management with prolotherapy. Headache. 1963;3:21–8 14031578 | Ineligible study design or publication type
30. | Kersschot J. Low-Dose Dextrose Prolotherapy as Effective as High-Dose Dextrose Prolotherapy in the Treatment of Lateral Epicondylitis? A Double-Blind, Ultrasound Guided, Randomized Controlled Study. Archives of physical medicine and rehabilitation. 2023;104(7):1154–1155. Comment on: Arch Phys Med Rehabil. 2023 Feb;104(2):179–187 PMID: 36243123 [https://www.ncbi.nlm.nih.gov/pubmed/36243123] Comment in: Arch Phys Med Rehabil. 2023 Jul;104(7):1155–1156 PMID: 36990377 [https://www.ncbi.nlm.nih.gov/pubmed/36990377]36990375 | Ineligible study design or publication type
31. | Khalil SI. Effect of Perineural Dextrose Injection on Myofascial Pain Syndrome. Article. Al-Anbar Med J. 2022;18(2):61–65 | Ineligible intervention
32. | Khan SA, Kumar A, Varshney MK, Trikha V, Yadav CS. Dextrose prolotherapy for recalcitrant coccygodynia. Journal of orthopaedic surgery (Hong Kong). 2008;16(1):27–9. Comment in: J Orthop Surg (Hong Kong). 2008 Aug;16(2):270; author reply 270 PMID: 18725689 [https://www.ncbi.nlm.nih.gov/pubmed/18725689]18453654 | Ineligible study design or publication type
33. | Kidd R. Re: Yelland MJ, Glasziou PP, Bogduk N, . Prolotherapy injections, saline injections, and exercises for chronic low-back pain: a randomized study. Spine. 2003;29:9–16. Spine. 2004;29(16):1841–3. Comment on: Spine (Phila Pa 1976). 2004 Jan 1;29(1):9–16; discussion 16 PMID: 14699269 [https://www.ncbi.nlm.nih.gov/pubmed/14699269]14699269 | Ineligible study design or publication type
34. | Kiliç SC, Güngörmüş M. Is dextrose prolotherapy superior to placebo for treatment of TMJ hypermobility: Comparison of pain changes at masseter, lateral pterygoid, sternocleidomastoid and trapezius muscles. Article. Curr Res Dent Sci. 2022;32(3):226–230 | Not published in English
35. | Kim JE, Yi YH, Lee SY, Kim YJ, Lee JG, Cho BM. The efficacy of ten weeks prolotherapy as add-on therapy in the treatment of chronic low back pain. Kuwait Medical Journal. 2016;48(3):215–218 | Unable to locate PDF
36. | Kishore S, Ravi P, Dominic D, Gnanapragasam R. COMPARISON OF EFFECTIVENESS OF PROLOTHERAPY AND CORRECTIVE EXERCISE PROGRAM VS PROLOTHERAPY AND ISOMETRICS STRENGTHENING ON PAIN AND FUNCTIONAL IMPROVEMENT IN SUPRASPINATUS TENDINOPATHY IN A TERTIARY CARE CENTRE. Article. Cent Eur J Sport Sci Med. 2023;42(2):65–73 | Ineligible intervention
37. | Koehn G, Jackson L, Ablah E, Okut H, Porter A. Use of UltrasoundGuided Tendon Fenestration and Injection Procedures for Treatment of Tendinosis. Kansas journal of medicine. 2023;16:258–260 37954879 | Ineligible outcome
38. | Köroğlu Ö, Örsçelik A, Karasimav Ö, Demir Y, Solmaz I. Is 5% dextrose prolotherapy effective for radicular low back pain? Article. Gulhane Med J. 2019;61(3):123–127 | Ineligible intervention
39. | Lee HS, Jo DH, Kim MG, Kim MH, Park SH, Chung SH. Comparision of remifentanil and remifentanil/midazolam for outpatient anesthesia in prolotherapy. Korean journal of anesthesiology. 2009;56(2):175–180 30625718 | Not published in English
40. | Lin C-L, Yang M-T, Lee Y-H, Chen Y-W, Vitoonpong T, Huang S-W. Comparison of Clinical and Ultrasound Imaging Outcomes Between Corticosteroid and Hypertonic Dextrose Injections for Chronic Supraspinatus Tendinopathy. Orthopaedic journal of sports medicine. 2022;10(11):23259671221129603 36419476 | Ineligible study design or publication type
41. | Lin M-T, Liao C-L, Hsiao M-Y, Hsueh H-W, Chao C-C, Wu C-H. Volume Matters in Ultrasound-Guided Perineural Dextrose Injection for Carpal Tunnel Syndrome: A Randomized, Double-Blinded, Three-Arm Trial. Frontiers in pharmacology. 2020;11:625830 33391002 | Ineligible intervention
42. | Lin M-T, Liu IC, Syu W-T, Kuo P-L, Wu C-H. Effect of Perineural Injection with Different Dextrose Volumes on Median Nerve Size, Elasticity and Mobility in Hands with Carpal Tunnel Syndrome. Diagnostics (Basel, Switzerland). 2021;11(5) | Ineligible intervention
43. | Liu S, Pollock JE, Mulroy MF, Allen HW, Neal JM, Carpenter RL. Comparison of 5% with dextrose, 1.5% with dextrose, and 1.5% dextrose-free lidocaine solutions for spinal anesthesia in human volunteers. Anesthesia and analgesia. 1995;81(4):697–702 7573996 | Ineligible intervention
44. | Loeser JD. Prolotherapy Injections, Saline Injections, and Exercises for Chronic Low-Back Pain: A Randomized Trial - Point of View. Note. Spine. 2004;29(1):16 14699269 | Ineligible study design or publication type
45. | Louw F. The occasional prolotherapy for lateral epicondylosis (tennis elbow). Canadian journal of rural medicine : the official journal of the Society of Rural Physicians of Canada = Journal canadien de la medecine rurale : le journal officiel de la Societe de medecine rurale du Canada. 2014;19(1):31–3 24398356 | Ineligible study design or publication type
46. | Maniquis-Smigel L, Dean Reeves K, Jeffrey Rosen H, . Short Term Analgesic Effects of 5% Dextrose Epidural Injections for Chronic Low Back Pain: A Randomized Controlled Trial. Anesthesiology and pain medicine. 2017;7(1):e42550 28920043 | Ineligible intervention
47. | Mansiz-Kaplan B, Nacir B, Pervane-Vural S, Tosun-Meric O, Duyur-Cakit B, Genc H. Effect of Perineural Dextrose Injection on Ulnar Neuropathy at the Elbow: A Randomized, Controlled, Double-Blind Study. Archives of physical medicine and rehabilitation. 2022;103(11):2085–2091 35690093 | Ineligible intervention
48. | Martinez-Barro D, Rivera-Bello JD, Cruz-Lopez JM, Hernandez-Amaro H, Rojano-Mejia D. [Functionality/isokinetic work of quadriceps in patients with gonarthrosis managed with prolotherapy]. Funcionalidad/trabajo isocinetico de cuadriceps de pacientes con gonartrosis manejados con proloterapia. 2023;61(6):788–795 | Not published in English
49. | Martinez-Pizarro S. Prolotherapy With Dextrose To Reduce Pain In Osteoarthritis Of The Knee. Proloterapia con dextrosa para reducir el dolor en la osteoartritis de rodilla. 2020; | Ineligible study design or publication type
50. | McNair PJ, Marshall RN, Maguire K, Brown C. Knee joint effusion and proprioception. Article. Archives of Physical Medicine and Rehabilitation. 1995;76(6):566–568 7763157 | Ineligible intervention
51. | Medin Ceylan C, Sahbaz T, Cigdem Karacay B. Demonstrating the effectiveness of Platelet Rich Plasma and Prolotherapy treatments in knee osteoarthritis. Irish journal of medical science. 2023;192(1):193–198 36166187 | Ineligible intervention
52. | Memis S. Evaluation of the effects of prolotherapy on condyles in temporomandibular joint hypermobility using fractal dimension analysis. Journal of the Korean Association of Oral and Maxillofacial Surgeons. 2022;48(1):33–40 35221305 | Ineligible outcome
53. | Merriman JR. PROLOTHERAPY VERSUS OPERATIVE FUSION IN THE TREATMENT OF JOINT INSTABILITY OF THE SPINE AND PELVIS. The Journal of the International College of Surgeons. 1964;42:150–9 14203402 | Ineligible study design or publication type
54. | Miller MR, Mathews RS, Reeves KD. Treatment of painful advanced internal lumbar disc derangement with intradiscal injection of hypertonic dextrose. Pain physician. 2006;9(2):115–21 16703971 | Ineligible study design or publication type
55. | Mistraletti G, De La Cuadra-Fontaine JC, Asenjo FJ, . Comparison of Analgesic Methods for Total Knee Arthroplasty: Metabolic Effect of Exogenous Glucose. Article. Reg Anesth Pain Med. 2006;31(3):260–269 16701193 | Ineligible intervention
56. | Murphy GS, Avram MJ, Greenberg SB, . Perioperative Methadone and Ketamine for Postoperative Pain Control in Spinal Surgical Patients: A Randomized, Double-blind, Placebo-controlled Trial. Anesthesiology. 2021;134(5):697–708. Comment in: Anesthesiology. 2021 May 1;134(5):676–679 PMID: 33740051 [https://www.ncbi.nlm.nih.gov/pubmed/33740051]33730151 | Ineligible intervention
57. | Myers A. Prolotherapy treatment of low back pain and sciatica. Bulletin of the Hospital for Joint Diseases. 1961;22:48–55 14477661 | Ineligible study design or publication type
58. | Nair A. Prolotherapy as an intervention for chronic, refractory musculoskeletal pain. Saudi journal of anaesthesia. 2021;15(4):463–465 34658744 | Ineligible study design or publication type
59. | Nasiri A, Rezaei Motlagh F, Vafaei MA. Efficacy comparison between ultrasound-guided injections of 5% dextrose with corticosteroids in carpal tunnel syndrome patients. Article. Neurol Res. 2023;45(6):554–563 36617808 | Ineligible intervention
60. | Nourani BB. Osteopathic considerations in sports medicine: Prolotherapy for knee pain with enthesopathy. Found of Osteopat Med: Philos, Sci, Clin publication type Appl, and Res: Fourth Ed. 2018; | Ineligible study design or publication type
61. | Pereira Pires JA, Rey Moura EC, Oliveira CMBd, Vieira Dibai-Filho A, Soares Brandao Nascimento MdD, Cunha Leal P. Hypertonic glucose in the treatment of low back pain: A randomized clinical trial. Medicine. 2023;102(38):e35163 37747016 | Ineligible intervention
62. | Rabago D, Kijowski R, Woods M, . Association between disease-specific quality of life and magnetic resonance imaging outcomes in a clinical trial of prolotherapy for knee osteoarthritis. Archives of physical medicine and rehabilitation. 2013;94(11):2075–82 23850615 | Ineligible outcome
63. | Rabago D, Mundt M, Zgierska A, Grettie J. Hypertonic dextrose injection (prolotherapy) for knee osteoarthritis: Long term outcomes. Complementary therapies in medicine. 2015;23(3):388–95 26051574 | Ineligible outcome
64. | Rabago D, Patterson JJ. Prolotherapy: an effective adjunctive therapy for knee osteoarthritis. The Journal of the American Osteopathic Association. 2013;113(2):122–3. Comment on: J Am Osteopath Assoc. 2012 Nov;112(11):709–15 PMID: 23139341 [https://www.ncbi.nlm.nih.gov/pubmed/23139341]23412672 | Ineligible study design or publication type
65. | Rabago D, Patterson JJ, Mundt M, . Dextrose and morrhuate sodium injections (prolotherapy) for knee osteoarthritis: a prospective open-label trial. Journal of alternative and complementary medicine (New York, NY). 2014;20(5):383–91 | Ineligible study design or publication type
66. | Reeves KD, Hassanein K. Randomized, prospective, placebo-controlled double-blind study of dextrose prolotherapy for osteoarthritic thumb and finger (DIP, PIP, and trapeziometacarpal) joints: evidence of clinical efficacy. Journal of alternative and complementary medicine (New York, NY). 2000;6(4):311–20 | Ineligible intervention
67. | Remvig L, Jensen KE. MRI outcomes in prolotherapy for lateral epicondylosis. Letter. Int Musculoskelet Med. 2011;33(1):37–38 | Ineligible study design or publication type
68. | Ryan M, Wong A, Taunton J. Favorable outcomes after sonographically guided intratendinous injection of hyperosmolar dextrose for chronic insertional and midportion achilles tendinosis. AJR American journal of roentgenology. 2010;194(4):1047–53 20308509 | Ineligible outcome
69. | Schwartz RG, Sagedy N. Prolotherapy: A literature review and retrospective study. Journal of Neurological and Orthopaedic Medicine and Surgery. 1991;12(3):220–223 | Ineligible intervention
70. | Sert AT, Ozcan E, Esmaeilzadeh S. Poster 383 Effects of Dextrose Prolotherapy in the Treatment of Patients with Knee Osteoarthritis: A Randomized Controlled Trial. PM & R : the journal of injury, function, and rehabilitation. 2016;8(9S):S286 | Ineligible study design or publication type
71. | Shen Y-P, Li T-Y, Chou Y-C, . Comparison of perineural platelet-rich plasma and dextrose injections for moderate carpal tunnel syndrome: A prospective randomized, single-blind, head-to-head comparative trial. Journal of tissue engineering and regenerative medicine. 2019;13(11):2009–2017 31368191 | Ineligible intervention
72. | Solmaz I, Orscelik A, Koroglu O. Modified prolotherapy by 5% dextrose: Two years experiences of a traditional and complementary medicine practice center in Turkey. Journal of back and musculoskeletal rehabilitation. 2022;35(4):763–770 34957982 | Ineligible intervention
73. | Soneral S. Effective use of dextrose-prolotherapy within the scope of osteopathic family medicine. Osteopathic Family Physician. 2015;7(4):8–12. | Ineligible study design or publication type
74. | Suputtitada A, Chen J-L, Wu C-K, Peng Y-N, Yen T-Y, Chen CPC. Determining the Most Suitable Ultrasound-Guided Injection Technique in Treating Lumbar Facet Joint Syndrome. Biomedicines. 2023;11(12) | Ineligible intervention
75. | Taskesen F, Cezairli B. Efficacy of prolotherapy and arthrocentesis in management of temporomandibular joint hypermobility. Cranio : the journal of craniomandibular practice. 2023;41(5):423–431 33326351 | Ineligible intervention
76. | Trescot A, Brown M. Peripheral nerve entrapment, hydrodissection, and neural regenerative strategies. Techniques in Regional Anesthesia and Pain Management. 2015;19(1–2):85–93 | Ineligible intervention
77. | Tsatsos G, Mandal R. Prolotherapy in the treatment of foot problems. Journal of the American Podiatric Medical Association. 2002;92(6):366–8 12070238 | Ineligible study design or publication type
78. | Ugurlar M, Sonmez MM, Ugurlar OY, Adiyeke L, Yildirim H, Eren OT. Effectiveness of Four Different Treatment Modalities in the Treatment of Chronic Plantar Fasciitis During a 36-Month Follow-Up Period: A Randomized Controlled Trial. The Journal of foot and ankle surgery : official publication of the American College of Foot and Ankle Surgeons. 2018;57(5):913–918 30149850 | Ineligible intervention
79. | Uzun Ş, Karagöz AH, Köse EA, Canbay Ö, Özgen S. The effect of dexmedetomidine diluted in 5 % dextrose to prevent propofol injection pain. Article. Anestezi Derg. 2009;17(4):201–204 | Ineligible intervention
80. | Watson JD, Shay BL. Treatment of chronic low-back pain: a 1-year or greater follow-up. Journal of alternative and complementary medicine (New York, NY). 2010;16(9):951–8 | Ineligible intervention
81. | Wilkinson HA. Injection therapy for enthesopathies causing axial spine pain and the “failed back syndrome”: a single blinded, randomized and cross-over study. Pain physician. 2005;8(2):167–73 16850071 | Ineligible intervention
82. | Won SJ, Kim D-Y, Kim JM. Effect of platelet-rich plasma injections for chronic nonspecific low back pain: A randomized controlled study. Medicine. 2022;101(8):e28935 35212300 | Ineligible intervention
83. | Yelland M, Hooper A, Faris P. Minimum clinically important changes in disability in a prospective case series with chronic thoracic and lumbar spinal pain. Article. Int Musculoskelet Med. 2011;33(2):49–53 | Ineligible study design or publication type
84. | Yelland MJ, Del Mar C, Pirozzo S, Schoene ML, Vercoe P. Prolotherapy injections for chronic lowback pain. Short survey. Praxis. 2004;93(39):1597 | Ineligible study design or publication type
85. | Yelland MJ, Schluter PJ. Defining worthwhile and desired responses to treatment of chronic low back pain. Pain medicine (Malden, Mass). 2006;7(1):38–45 16533195 | Ineligible outcome