# APPENDIX B ONGOING AND COMPLETED TRIALS (WITHOUT PUBLICATIONS)

Trial # | Study Title | Status | Total N* | Location
NCT00674622 | Prolotherapy for the Treatment of Chronic Lateral Epicondylitis | Completed (no publication) | 67 | Pittsburgh, Pennsylvania, USA
NCT05429827 | The Therapeutic Effects of Dextrose Injection for Myofascial Pain Syndrome | Recruiting (no publication) | 30 | Tainan, Taiwan
NCT05239091 | Comparison of the Efficacy of Prolotherapy Injection Therapy & Local Anesthetic Injection Therapy | Completed (no publication) | 28 | Istanbul, Turkey
NCT05326763 | Functional and Electromyographical Changes After PRP or Dextrose Injection in Chronic Lateral Epicondylitis | Unknown (no publication) | 90 | Tainan, Taiwan
NCT00835939 | Treatment for Achilles Tendinopathy | Unknown (no publication) | 17 | Calgary, Alberta, Canada
NCT05966948 | HDP vs NS Intra-articular Injection Among KOA With Obese Patient | Completed (no publication) | 40 | Surabaya, East Java, Indonesia
NCT05220527 | Effects of Knee Injections on Patients With Knee Osteoarthritis | Unknown (no publication) | 60 | Taipei, Taiwan
NCT06345222 | Examining the Effect of Prolotherapy on Quality of Life and Painkiller Use in Patients With Knee Pain | Completed (no publication) | 65 | Bursa, Turkey
NCT06301958 | Dextrose Prolotherapy on Articular Cartilage | Recruiting (no publication) | 60 | Chiayi City, Taiwan
NCT04178304 | Effect of Prolotherapy in Knee Osteoarthritis | Completed (no publication) | 63 | Alexandria, Egypt
NCT03942640 | Perineural Injection and Supraspinatus Tendinopathy | Unknown (no publication) | 60 | Mansoura, Egypt
NCT04478344 | Ultrasound Localization and Guided Injection for Superior Cluneal Nerve Entrapment | Recruiting (no publication) | 30 | Taipei, Taiwan
NCT03174080 | PET MRI for Evaluation of Knee Osteoarthritis in Patients With Bilateral Knee OA | Unknown (no publication) | 150 | Tel Aviv, Israel
NCT02052089 | Comparative Study for the Optimal Treatment Method of Lateral Epicondylosis | Completed (no publication) | 231 | Seoul, Republic of Korea
NCT00685880 | Prolotherapy Versus Steroids for Thumb Carpometacarpal Joint Arthritis | Terminated (no publication) | 2 | Rochester, Minnesota, USA
NCT04941118 | Myofascial Pain Syndrome and Dextrose Prolotherapy | Unknown (no publication) | 60 | Hatay, Turkey
NCT05160532 | Intraarticular Dextrose Prolotherapy for Symptomatic Knee Osteoarthritis | Recruiting (no publication) | 160 | Scottsdale, Arizona, USA
NCT04319406 | Comparative Efficacy of Prolotherapy and Dry Needling in Management of ADD | Unknown (no publication) | 50 | Rohtak, Haryana, India
NCT03675659 | Intra-articular Magnesium Sulfate for TMJ Dysfunction | Unknown (no publication) | 100 | Giza, Egypt
NCT04805242 | Effects of Dextrose Prolotherapy in Rotator Cuff Disease | Unknown (no publication) | 60 | Istanbul, Turkey
NCT05984121 | Comparison of the Effectiveness of Local Ozone Injection and Dextrose Prolotherapy Injection in Chronic Plantar Fasciitis | Completed (no publication) | 60 | Kirsehir, Turkey
NCT04165902 | Additional Effects of Steroid and Dextrose to Hyaluronic Acid on Knee Osteoarthritis | Unknown (no publication) | 60 | Taipei, Taiwan
NCT06161038 | Precision Medicine for Nociception, Sngception and Proprioception. | Recruiting (no publication) | 160 | Taipei, Taiwan
NCT01761838 | The Underlying Mechanism of Spinal Manipulative Therapy and the Effect of Pain on Physical Outcome Measures | Completed (no publication) | 103 | Edmonton, Alberta, Canada
NCT05548738 | Caudal Epidural Prolotherapy Versus Steroids in Failed Back Surgery Syndrome | Active, Not Recruiting (no publication) | 80 | Alexandria, Egypt
NCT03161210 | Evaluation of Pain Regression in Patients With Myofascial Facial Pain Using Dextrose, Local Anaesthesia and Saline. | Unknown (ineligible publication) | 80 | Cairo, Egypt
NCT05154695 | Precision Medicine for Sng/Pain Control | Recruiting (no publication) | 88 | Taipei, Taiwan
NCT05416255 | Measuring Synovial Fluid Components | Active, Not Recruiting (no publication) | 80 | Rosario, Santa Fe, Argentina
NCT04006314 | Platelet Rich Plasma and Neural Prolotherapy Injections in Treating Knee Osteoarthritis | Unknown (no publication) | 24 | Taoyuan, Taiwan
NCT01934868 | Prolotherapy Versus Epidural Steroid Injections (ESI) for Lumbar Pain Radiating to the Leg | Completed (no publication) | 110 | Jerusalem, Israel
NCT04062838 | Prolotherapy for the Treatment of Partial Rotator Cuff Tears | Withdrawn (no publication) | 0 | Jerusalem, Israel
NCT04796103 | The Effectiveness of Prolotherapy (%5 Dextrose) in the Treatment of Patients With Chondromalacia Patella | Completed (no publication) | 52 | Ankara, Turkey
NCT05688787 | Efficacy of Perineural Injection Therapy in Primary Fibromyalgia | Not Yet Recruiting (no publication) | 60 | Cairo, Egypt
NCT06308887 | Comparison of Ultrasound-Guided Perimeniscal Steroid and 5% Dextrose Injections in Knee Osteoarthritis | Completed (protocol only) | 31 | Kastamonu, Turkey
NCT04088045 | High Frequency Intensive Autologous PRP Injection and Genicular Nerve Blocks in Treating Knee Osteoarthritis | Unknown (no publication) | 36 | Taoyuan, Taiwan
NCT06063356 | Effects of Dextrose Prolotherapy in Patients With Knee Osteoarthritis | Active, Not Recruiting (no publication) | 66 | Istanbul, Turkey
NCT03000205 | Effects of Hypertonic Dextrose Water Injection for Supraspinatus Tendinosis Patients | Completed (no publication) | 60 | New Taipei City, Taiwan
NCT04557878 | Role of Liquid Phase Concentrated Growth Factors vs. Hypertonic Dextrose Prolotherapy for Management of Patients With Disc Displacement Without Reduction | Unknown (ineligible publication) | 24 | Alexandria, Egypt
NCT02116075 | Caudal Corticosteroid vs. Dextrose Injection for Lumbosacral Radicular Pain. | Unknown (no publication) | 50 | Long Beach, California, USA
NCT04212975 | Arthrocentesis Followed by Prolotherapy | Unknown (no publication) | 60 | Cairo, Egypt
NCT03411811 | Ulnar Wrist Pain Treatment With Dextrose Prolotherapy | Unknown (no publication) | 60 | Rosario, Santa Fe, Argentina
NCT03690232 | Intra-articular Glucose Versus Hyaluronic Acid Injection for Knee Osteoarthrosis | Unknown (no publication) | 100 | Taipei, Taiwan
NCT05279937 | The Ultrasound-Guided Dextrose Prolotherapy in Ehlers-Danlos Syndrome Patients | Not Yet Recruiting | 40 | New Orleans, Louisiana, USA
NCT05821985 | Evaluation of the Effect of Dextrose Prolotherapy Versus Dry Needling Therapy | Completed (no publication) | 40 | Bani Suwayf, Egypt
NCT01897259 | Comparison of Conservative Methods for the Treatment of Lateral Epicondylitis: A Randomized, Prospective Study | Unknown (no publication) | 200 | Louisville, Kentucky, USA
NCT05066451 | 5% and 15% Dextrose Prolotherapy Efficacy in Lateral Epicondylitis | Completed (no publication) | 26 | Istanbul, Turkey
NCT02492945 | Bundang Rehabilitative Impact Study of the Elbow Epicondylitis | Completed (no publication) | 40 | SeongNam-Si, Gyeonggi-Do, Republic of Korea
NCT04916353 | Effects of Ultrasound-guide Hypertonic Dextrose Injection for Chronic Subacromial Bursitis | Unknown (no publication) | 60 | New Taipei City, Taiwan
NCT01326351 | Prolotherapy for the Treatment of Plantar Fasciitis | Unknown (no publication) | 60 | Moncton, New Brunswick, Canada