# APPENDIX A SEARCH STRATEGIES

Search Date: 02/02/24 | | Search Statement | Results
MEDLINE | 1 | Prolotherapy/ or (prolotherap* or proliferation therap* or regenerative injection*).ti,ab,kf. | 474
MEDLINE | 2 | (dextrose adj1 inject*).ti,ab,kf. | 460
MEDLINE | 3 | Injections, Intra-Articular/ or ((intra-articular or intra-articular or intra-coxal or intracoxal or intra-synovial or intrasynovial or joint* or orthobiologic*) adj1 (administration or deliver* or infusion* or inject*)).ti,ab,kf. | 14323
MEDLINE | 4 | exp Spine/ or (columna dorsis or dorsal column or interspinous or intervertebral or spinal or spine or spinous or vertebra*).ti,ab,kf. | 651336
MEDLINE | 5 | 3 or 4 | 664824
MEDLINE | 6 | Glucose/ or dextrose.ti,ab,kf. | 190062
MEDLINE | 7 | 5 and 6 | 1390
MEDLINE | 8 | 1 or 2 or 7 | 2192
MEDLINE | 9 | 8 not (Animals/ not (Animals/ and Humans/) | 1532

Search Date: 02/06/24 | | Search Statement | Results
EMBASE | 1 | Prolotherapy/ or (prolotherap* or proliferation therap* or regenerative injection*).ti,ab,kf. | 824
EMBASE | 2 | (dextrose adj1 inject*).ti,ab,kf. | 500
EMBASE | 3 | exp Intra-articular Drug Administration/ or ((intra-articular or intra-articular or intra-coxal or intracoxal or intra-synovial or intrasynovial or joint* or orthobiologic*) adj1 (administration or deliver* or infusion* or inject*)).ti,ab,kf. | 18263
EMBASE | 4 | exp Spine/ or (columna dorsis or dorsal column or interspinous or intervertebral or spinal or spine or spinous or vertebra*).ti,ab,kf. | 871789
EMBASE | 5 | 3 or 4 | 888905
EMBASE | 6 | Glucose/ or dextrose.ti,ab,kf. | 564031
EMBASE | 7 | 5 and 6 | 5672
EMBASE | 8 | 1 or 2 or 7 | 6827
EMBASE | 9 | 8 not ((exp Animal/ or Nonhuman) not exp Human/) | 5203
EMBASE | 10 | Limit 9 to (article or article in press or “review”) | 3473

Search Date: 02/02/24 | | Search Statement | Results
SCOPUS | 1 | TITLE-ABS-KEY(prolotherap* or (proliferation W/1 therap*) or (regenerative W/1 inject*)) | 1238
SCOPUS | 2 | TITLE-ABS-KEY(dextrose W/1 inject*) | 625
SCOPUS | 3 | TITLE-ABS-KEY((intra-articular or intra-articular or intra-coxal or intracoxal or intra-synovial or intrasynovial or joint* or orthobiologic*) W/1 (administration or deliver* or infusion* or inject*)).ti,ab,kf. | 19222
SCOPUS | 4 | TITLE-ABS-KEY(“columna dorsis” or “dorsal column” or interspinous or intervertebral or spinal or spine or spinous or vertebra*) | 1010307
SCOPUS | 5 | #3 or #4 | 1028104
SCOPUS | 6 | TITLE-ABS-KEY(dextrose) | 21834
SCOPUS | 7 | #5 and #6 | 438
SCOPUS | 8 | 1 or 2 or 7 | 2109
SCOPUS | 9 | TITLE-ABS-KEY(mouse or mice or rat or rats or rodent*) | 4406856
SCOPUS | 10 | #8 and not #9 | 1869
| | Total | 6,874
| | Total after deduplication | 4,742