# References

1 Linsky A, Gellad WF, Linder JA, Friedberg MW. Advancing the science of deprescribing: a novel comprehensive conceptual framework. J Am Geriatr Soc. 2019;67(10):2018–2022.31430394
2 National Center for Health Statistics (US). United States, 2016: With Chartbook on Long-Term Trends in Health. Hyattsville, MD: National Center for Health Statistics (US); 2017 Report 2017-1232.
3 Mangin D, Bahat G, Golomb BA, Mallery LH, Moorhouse P, Onder G, . International Group for Reducing Inappropriate Medication Use & Polypharmacy (IGRIMUP): position statement and 10 recommendations for action. Drugs Aging. 2018;35(7):575–587.30006810
4 Scott IA, Anderson K, Freeman CR, Stowasser DA. First do no harm: a real need to deprescribe in older patients. Med J Aust. 2014;201(7):390–392.25296059
5 Reeve E, Bell JS, Hilmer SN. Barriers to optimising prescribing and deprescribing in older adults with dementia: a narrative review. Curr Clin Pharmacol. 2015;10(3):168–177.26338170
6 Reeve E, Shakib S, Hendrix I, Roberts MS, Wiese MD. Review of deprescribing processes and development of an evidence-based, patient-centered deprescribing process. Br J Clin Pharmacol. 2014;78:738–747.24661192
7 Thompson W, Farrell B. Deprescribing: what is it and what does the evidence tell us? Can J Hosp Pharm. 2013;66:201.23814291
8 Higgins JP, Green S. Cochrane Handbook for Systematic Reviews of Interventions Version 5.1.0 [updated March 2011]. The Cochrane Collaboration. 2011;Available from http://handbook.cochrane.org. (accessed July 23, 2019)
9 Higgins JP Thompson SG, Deeks JJ, Altman DG. Measuring inconsistency in meta-analyses. BMJ. 2003;327:557–560.12958120
10 Cohen J. Statistical power analysis for the behavioral sciences (2nd ed.). Hillsdale, NJ: Lawrence Earlbaum Associates. 1988.
11 Underwood M, Barnett A, Hajioff S. Cluster randomisation: a trap for the unwary. Br J Gen Pract. 1998;48:1089–1090.9624757
12 GRADEpro GDT: GRADEpro Guideline Development Tool [Software]. Ontario, Canada: McMaster University and Evidence Prime, Inc., 2015.
13 Schünemann H, Brozek J, Guyatt G, Oxman A, eds. GRADE handbook for grading quality of evidence and strength of recommendations. The GRADE Working Group, 2013. Available from https://gdt.gradepro.org/app/handbook/handbook.html. (accessed September 10, 2019).
14 Allard J, Hebert R, Rioux M, Asselin J, Voyer L. Efficacy of a clinical medication review on the number of potentially inappropriate prescriptions prescribed for community-dwelling elderly people. CMAJ. 2001;164(9):1291–1296.11341138
15 Avorn J, Soumerai SB, Everitt DE, Ross-Degnan D, Beers MH, Sherman D, . A randomized trial of a program to reduce the use of psychoactive drugs in nursing homes. N Engl J Med. 1992;327(3):168–173.1608408
16 Batty GM, Hooper R, Oborne CA, Jackson SHD. Investigating intervention strategies to increase the appropriate use of benzodiazepines in elderly medical in-patients. Br J Clin Governance. 2001;6(4):252–258.
17 Beer C, Loh PK, Peng YG, Potter K, Millar A. A pilot randomized controlled trial of deprescribing. Ther Adv Drug Saf. 2011;2(2):37–43.25083200
18 Bladh L, Ottosson E, Karlsson J, Klintberg L, Wallerstedt SM. Effects of a clinical pharmacist service on health-related quality of life and prescribing of drugs: a randomised controlled trial. BMJ Qual Saf. 2011;20(9):738–746.
19 Bonnet-Zamponi D, d’Arailh L, Konrat C, Delpierre S, Lieberherr D, Lemaire A, . Drug-related readmissions to medical units of older adults discharged from acute geriatric units: Results of the optimization of medication in AGEd multicenter randomized controlled trial. J Am Ger Soc. 2013;61(1):113–121.
20 Boyé NDA, Van der Velde N, De Vries OJ, Van Leshout EMM, Harthold KA, Mattace-Raso FUS, . Effectiveness of medication withdrawal in older fallers: results from the Improving Medication Prescribing to reduce Risk Of FALLs (IMPROveFALL) trial. Age Ageing. 2017;46(1):142–146.28181639
21 Bregnhoj L, Thirstrup S, Kristensen MB, Bjerrum L, Sonne J. Combined intervention programme reduces inappropriate prescribing in elderly patients exposed to polypharmacy in primary care. Eur J Clin Pharmacol. 2009;65(2):199–207.18807252
22 Briggs S, Pearce R, Dilworth S, Higgins I, Hullick C, Attia J. Clinical pharmacist review: A randomised controlled trial. Emerg Med Australas. 2015;27(5):419–426.26190132
23 Burns A, Furniss L, Cooke J, Lloyd Craig SK, Scobie S. Pharmacist medication review in nursing homes: a cost analysis. Int J Geriatr Psychopharmacol. 2000;2(3):137–141.
24 Campins L, Serra-Prat M, Gozalo I, Lopez D, Palomero E, Agusti C, . Randomized controlled trial of an intervention to improve drug appropriateness in community-dwelling polymedicated elderly people. Fam Pract. 2017;34(1):36–42.27605543
25 Campins L, Serra-Prat M, Palomera E, Bolibar I, Martinez MA, Gallo P. Reduction of pharmaceutical expenditure by a drug appropriateness intervention in polymedicated elderly subjects in Catalonia (Spain). Gac Sanit. 2019;33(2):106–111.29162290
26 Clyne B, Smith SM, Hughes CM, Boland F, Bradley MC, Cooper JA, . Effectiveness of a multifaceted intervention for potentially inappropriate prescribing in older patients in primary care: a cluster-randomized controlled trial (OPTI-SCRIPT Study). Ann Fam Med. 2015;13(6):545–553.26553894
27 Clyne B, Smith SM, Hughes CM, Boland F, Cooper JA, Fahey T. Sustained effectiveness of a multifaceted intervention to reduce potentially inappropriate prescribing in older patients in primary care (OPTI-SCRIPT study). Implement Sci. 2016;11(1):79.27255504
28 Coleman EA, Grothaus LC, Sandhu N, Wagner EH. Chronic care clinics: a randomized controlled trial of a new model of primary care for frail older adults. J Am Geriatr Soc. 1999;47(7):775–783.10404919
29 Cool C, Cestac P, McCambridge C, de Souto Barreto P, Rolland Y, . Reducing potentially inappropriate drug prescribing in nursing home residents: effectiveness of a geriatric intervention. Br J Clin Pharmacol. 2018;84(7):1598–1610.29607568
30 Cossette B, Ethier JF, Joly-Mischlich T, Bergeron J, Ricard G, Brazeau S, . Reduction in targeted potentially inappropriate medication use in elderly inpatients: a pragmatic randomized controlled trial. Eur J Clin Pharmacol. 2017;73(10):1237–1245.28717929
31 Crotty M, Halbert J, Rowett D, Giles L, Birks R, Williams H, . An outreach geriatric medication advisory service in residential aged care: a randomised controlled trial of case conferencing. Age Ageing. 2004;33(6):612–617.15385274
32 Crotty M, Rowett D, Spurling L, Giles LC, Phillips PA. Does the addition of a pharmacist transition coordinator improve evidence-based medication management and health outcomes in older adults moving from the hospital to a long-term care facility? Results of a randomized, controlled trial. Am J Geriatr Pharmacother. 2004;2(4):257–264.15903284
33 Dalleur O, Boland B, Losseau C, Henrard S, Wouters D, Speybroeck N, . Reduction of potentially inappropriate medications using the STOPP criteria in frail older inpatients: a randomised controlled study. Drugs Aging. 2014;31(4):291–298.24566877
34 Denneboom W, Dautzenberg MG, Grol R, De Smet PA. Treatment reviews of older people on polypharmacy in primary care: cluster controlled trial comparing two approaches. Br J Gen Pract. 2007;57(542):723–731.17761060
35 Donovan JL, Kanaan AO, Thomson MS, Rochon P, Lee M, Gavendo L, . Effect of clinical decision support on psychotropic medication prescribing in the long-term care setting. J Am Geriatr Soc. 2010;58(5):1005–1007.20722841
36 Frankenthal D, Kalendaryev E, Lerman Y. Intervention with the screening tool of older persons potentially inappropriate prescriptions/screening tool to alert doctors to right treatment criteria in elderly residents of a chronic geriatric facility: a randomized clinical trial. J Am Geriatr Soc. 2014;62(9):1658–1665.25243680
37 Fried TR, Niehoff KM, Street RL, Charpentier PA, Rajeevan N, Miller PL, . Effect of the Tool to Reduce Inappropriate Medications on medication communication and deprescribing. J Am Geriatr Soc. 2017;65(10):2265–2271.28804870
38 Furniss L, Burns A, Craig SKL, Scobie S, Cooke J, Faragher B. Effects of a pharmacist’s medication review in nursing homes. Randomised controlled trial. Br J Psychiatry. 2000;176:563–567.10974963
39 Gallagher M. Evaluating a protocol to train hospice staff in administering individualized music. Int J Palliat Nurs. 2011;17(4):195–201.21537322
40 Garcia-Gollarte F, Baleriola-Julvez J, Ferrero-Lopez I, Cuenllas-Diaz A, Cruz-Jentoft AJ. An educational intervention on drug use in nursing homes improves health outcomes resource utilization and reduces inappropriate drug prescription. J Am Med Dir Assoc. 2014;15(12):885–891.24895001
41 Gillespie P, Clyne B, Raymakers A, Fahey T, Hughes CM, Smith SM. Reducing potentially inappropriate prescribing for older people in primary care: cost-effectiveness of the OPTI-SCRIPT intervention. Int J Technol Assess Health Care. 2017;33(4):494–503.29019297
42 Gillespie U, Alassaad A, Hammarlund-Udenaes M, Morlin C, Henrohn D, Bertilsson M, . Effects of pharmacists’ interventions on appropriateness of prescribing and evaluation of the instruments’ (MAI, STOPP and STARTs’) ability to predict hospitalization-analyses from a randomized controlled trial. PLoS One. 2013;8(5):e62401.23690938
43 Gnjidic D, Ong HMM, Leung C, Jansen J, Reeve E. The impact of in hospital patient-education intervention on older people’s attitudes and intention to have their benzodiazepines deprescribed: a feasibility study. TherAdv Drug Saf. 2019;10:1–11.
44 Gulla C, Flo E, Kjome RLS, Husebo BS. Deprescribing antihypertensive treatment in nursing home patients and the effect on blood pressure. J Geriatr Cardiol. 2018;15(4):275–283.29915617
45 Gustafsson M, Sjolander M, Pfister B, Schneede J, Lovheim H. Effects of pharmacists’ interventions on inappropriate drug use and drug-related readmissions in people with dementia-a secondary analysis of a randomized controlled trial. Pharmacy. 2018;6(1) pii: E7. doi: 10.3390/pharmacy6010007 29337859
46 Haag JD, Davis AZ, Hoel RW, Armon JJ, Odell LJ, Dierkhising RA, . Impact of pharmacist-provided medication therapy management on healthcare quality and utilization in recently discharged elderly patients. Am Health Drug Benefits. 2016;9(5):259–267.27625743
47 Hanlon JT, Weinberger M, Samsa GP, Schmader KE, Uttech KM, Lewis IK, . A randomized, controlled trial of a clinical pharmacist intervention to improve inappropriate prescribing in elderly outpatients with polypharmacy. Am J Med. 1996;100(4):428–437.8610730
48 Hellstrom LM, Bondesson A, Hoglund P, Midlov P, Holmdahl L, Rickhag E, . Impact of the Lund Integrated Medicines Management (LIMM) model on medication appropriateness and drug-related hospital revisits. Eur J Clin Pharmacol. 2011;67(7):741–752.21318595
49 Husebo BS, Ballard C, Aarsland D, Selbaek G, Slettebo DD, Gulla C,. The effect of a multicomponent intervention on quality of life in residents of nursing homes: a randomized controlled trial (COSMOS). J Am Med Dir Assoc. 2019;20:330–339.30630722
50 Jodar-Sanchez F, Malet-Larrea A, Martin JJ, Garcia-Mochón L, López del Amo MP, Martinez-Martinez F, . Cost-utility analysis of a medication review with follow-up service for older adults with polypharmacy in community pharmacies in Spain: the conSIGUE program. PharmacoEconomics. 2015;33(6):599–610.25774017
51 Juola AL, Bjorkman MP, Pylkkanen S, Finne-Soveri H, Soini H, Kautiainen H, . Feasibility and baseline findings of an educational intervention in a randomized trial to optimize drug treatment among residents in assisted living facilities. Eur Geriatr Med. 2014;5(3):195–199.
52 Juola AL, Bjorkman MP, Pylkkanen S, Finne-Soveri H, Soini H, Kautiainen H, . Nurse education to reduce harmful medication use in assisted living facilities: effects of a randomized controlled trial on falls and cognition. Drugs Aging. 2015;32(11):947–955.26446153
53 Köberlein-Neu J, Mennemann H, Hamacher S, Waltering I, Jaehde U, Schaffert C, . Interprofessional medication management in patients with multiple morbidities. Dtsch Arztebl Int. 2016;113(44):741–748.27890050
54 Krska J, Cromarty JA, Arris F, Jamieson D, Hansford D, Duffus PRS, . Pharmacist-led medication review in patients over 65: a randomized, controlled trial in primary care. Age Ageing. 2001;30(3):205–211.11443021
55 Kutner JS, Blatchford PJ, Taylor DH, Ritchie CS, Bull JH, Fairclough DL, . Safety and benefit of discontinuing statin therapy in the setting of advanced, life-limiting illness a randomized clinical trial. JAMA Int Med. 2015;175(5):691–700.
56 Kwint HF, Faber A, Gussekloo J, Bouvy ML. Effects of medication review on drug-related problems in patients using automated drug-dispensing systems: A pragmatic randomized controlled study. Drugs Aging. 2011;28(4):305–314.21428465
57 Lampela P, Hartikainen S, Lavikainen P, Sulkava R, Huupponen R. Effects of medication assessment as part of a comprehensive geriatric assessment on drug use over a 1-year period: a population-based intervention study. Drugs Aging. 2010;27(6):507–521.20524710
58 Lapane KL, Hughes CM, Christian JB, Daiello LA, Cameron KA, Feinberg J. Evaluation of the Fleetwood Model of long-term care pharmacy. J Am Med Dir Assoc. 2011;12(5):355–363.21450170
59 Legrain S, Tubach F, Bonnet-Zamponi D, Lemaire A, Aquini JP, Paillaud E, . A new multimodal geriatric discharge-planning intervention to prevent emergency visits and rehospitalizations of older adults: the optimization of medication in AGEd multicenter randomized controlled trial. J Am Geriatr Soc. 2011;59(11):2017–2028.22091692
60 Lenaghan E, Holland R, Brooks A. Home-based medication review in a high risk elderly population in primary care-the POLYMED randomised controlled trial. Age Ageing. 2007;36(3):292–297.17387123
61 Lenssen R, Schmitz K, Griesel C, Heidenreich A, Schulz JP, Trautwein C, . Comprehensive pharmaceutical care to prevent drug-related readmissions of dependent-living elderly patients: a randomized controlled trial. BMC Geriatr. 2018;18(1):135.29898670
62 Malet-Larrea A, Goyenechea E, Garcia-Cardenas V, Calvo B, Arteche JM, Aranegui P, . The impact of a medication review with follow-up service on hospital admissions in aged polypharmacy patients. Br J Clin Pharmacol. 2016:82:831–838.27195696
63 Malet-Larrea A, Goyenechea E, Gastelurrutia MA, Calvo B, Garcia-Cardenas V, Cabases JM, . Cost analysis and cost-benefit analysis of a medication review with follow-up service in aged polypharmacy patients. Eur J Health Econ. 2017;18(9):1069–1078.27913940
64 Martin P, Tamblyn R, Benedetti A, Ahmed S, Tannenbaum C. Effect of a pharmacist-led educational intervention on inappropriate medication prescriptions in older adults: the D-PRESCRIBE randomized clinical trial. JAMA. 2018;320(18):1889–1898.30422193
65 McDerby N, Kosari SB, Bail K, Shield A. Peterson G, Naunton M. The effect of a residential care pharmacist on medication administration practices in aged care: A controlled trial. J Clin Pharm Ther. 2019:1–8.
66 Meador KG, Taylor JA, Thapa PB, Fought RL, Ray WA. Predictors of antipsychotic withdrawal or dose reduction in a randomized controlled trial of provider education. J Am Geriatr Soc. 1997;45(2):207–210.9033521
67 Meredith S, Feldman P, Frey D, Giammarco L, Hall K, Arnold K, . Improving medication use in newly admitted home healthcare patients: A randomized controlled trial. J Am Geriatr Soc. 2002;50(9):1484–1491.12383144
68 Michalek C, Wehling M, Schlitzer J, Frohnhofen H. Effects of “Fit fOR The Aged” (FORTA) on pharmacotherapy and clinical endpoints-a pilot randomized controlled study. Eur J Clin Pharmacol. 2014;70(10):1261–1267.25128076
69 Milos V, Rekman E, Bondesson A, Eriksson T, Jakobsson U, Westerlund T, . Improving the quality of pharmacotherapy in elderly primary care patients through medication reviews: a randomised controlled study. Drugs Aging. 2013;30(4):235–246.23408163
70 Moga DC, Abner EL, Rigsby DN, Eckmann L, Huffmyer M, Murphy RR, . Optimizing medication appropriateness in older adults: a randomized clinical interventional trial to decrease anticholinergic burden. Alzheimers Res Ther. 2017;9(1):36.28535785
71 Muth C, Uhlmann L, Haefeli WE, Rochon J, Van Den Akker M, Perera R, . Effectiveness of a complex intervention on Prioritising Multimedication in Multimorbidity (PRIMUM) in primary care: results of a pragmatic cluster randomised controlled trial. BMJ Open. 2018;8(2):e017740.
72 Olesen C, Harbig P, Buus KM, Barat I, Damsgaard EM. Impact of pharmaceutical care on adherence, hospitalisations and mortality in elderly patients. Int J Clin Pharm. 2014;36(1):163–171.24293339
73 Olsson IN, Runnamo R, Engfeldt P. Drug treatment in the elderly: an intervention in primary care to enhance prescription quality and quality of life. Scand J Prim Health Care. 2012;30(1):3–9.22175269
74 Patterson SM, Hughes CM, Cardwell C, Lapane KL, Murray AM, Crealey GE. A cluster randomized controlled trial of an adapted U.S. model of pharmaceutical care for nursing home residents in Northern Ireland (fleetwood Northern Ireland study): A cost-effectiveness analysis. J Am Geriatr Soc. 2011;59(4):586–593.21453379
75 Patterson SM, Hughes CM, Crealey G, Cardwell C, Lapane KL. An evaluation of an adapted U.S. model of pharmaceutical care to improve psychoactive prescribing for nursing home residents in Northern Ireland (Fleetwood Northern Ireland Study). J Am Geriatr Soc. 2010;58(1):44–53.20002510
76 Pazan F, Burkhardt H, Frohnhofen H, Weiss C, Throm C, Kuhn-Thiel A, . Changes in prescription patterns in older hospitalized patients: the impact of FORTA on disease-related over- and under-treatments. EurJ Clin Pharmacol. 2018;74(3):339–347.29196825
77 Pimlott NJG, Hux JE, Wilson LM, Kahan M, Li C, Rosser WW. Educating physicians to reduce benzodiazepine use by elderly patients: a randomized controlled trial. CMAJ. 2003;168(7):835–839.12668540
78 Pit SW, Byles JE, Henry DA, Holt L, Hansen V, Bowman DA. A quality use of medicines program for general practitioners and older people: a cluster randomised controlled trial. Med J Aust. 2007;187(1):23–30.17605699
79 Pitkala KH, Juola AL, Kautiainen H, Soini H, Finne-Soveri UH, Bell JS, . Education to reduce potentially harmful medication use among residents of assisted living facilities: a randomized controlled trial. J Am Med Dir Assoc. 2014;15(12):892–898.24814043
80 Polinder S, Boyé NDA, Mattace-Raso FUS, Van der Velde N, Hartholt KA, De Vries, OJ, . Cost-utility of medication withdrawal in older fallers: results from the improving medication prescribing to reduce risk of FALLs (IMPROveFALL) trial. BMC Geriatr. 2016;16(179).
81 Pope G, Wall N, Peters CM, O’Connor M, Saunders J, O’Sullivan C, . Specialist medication review does not benefit short-term outcomes and net costs in continuing-care patients. Age Ageing. 2011;40(3):307–312.20817937
82 Potter K, Flicker L, Page A, Etherton-Beer C. Deprescribing in frail older people: a randomised controlled trial. PLoS One. 2016;11(3):e0149984.26942907
83 Price M, Davies I, Rusk R, Lesperance M, Weber J. Applying STOPP guidelines in primary care through electronic medical record decision support: randomized control trial highlighting the importance of data quality. JMIR Med Inform. 2017;5(2):e15.28619704
84 Raebel MA, Charles J, Dugan J, Carroll NM, Korner EJ, Brand DW, . Randomized trial to improve prescribing safety in ambulatory elderly patients. J Am Geriatr Soc. 2007;55(7):977–985.17608868
85 Ravn-Nielsen LV, Duckert ML, Lund ML, Henriksen JP, Nielsen ML, Eriksen CS, . Effect of an in-hospital multifaceted clinical pharmacist intervention on the risk of readmission a randomized clinical trial. JAMA Int Med. 2018;178(3):375–382.
86 Richter CB, Berg A, Langner H, Meyer G, Köpke S, Balzer K, . Effect of person-centred care on antipsychotic drug use in nursing homes (EPCentCare): a cluster-randomised controlled trial. Age Ageing. 2019;0:1–7.
87 Rikala M, Korhonen MJ, Sulkava R, Hartikainen S. The effects of medication assessment on psychotropic drug use in the community-dwelling elderly. Int Psychogeriatr. 2011;23(3):473–484.20836913
88 Roberts MS, Stokes JA, King MA, Lynne TA, Purdie DM, Glasziou PP, . Outcomes of a randomized controlled trial of a clinical pharmacy intervention in 52 nursing homes. Br J Clin Pharmacol. 2001;51(3):257–265.11298072
89 Rognstad S, Brekke M, Fetveit A, Dalen I, Straand J. Prescription peer academic detailing to reduce inappropriate prescribing for older patients: a cluster randomised controlled trial. Br J Gen Pract. 2013;63(613):e554–562.23972196
90 Saltvedt I, Spigset O, Ruths S, Fayers P, Kaasa S, Sletvold O. Patterns of drug prescription in a geriatric evaluation and management unit as compared with the general medical wards: a randomised study. Eur J Clin Pharmacol. 2005;61(12):921–928.16307267
91 Schafer I, Kaduszkiewicz H, Mellert C, Loffler C, Mortsiefer A, Ernst A, . Narrative medicine-based intervention in primary care to reduce polypharmacy: results from the cluster-randomised controlled trial MultiCare AGENDA. BMJ Open. 2018;8(1):e017653.
92 Schmader KE, Hanlon JT, Landsman PB, Samsa GP, Lewis IK, Weinberger M. Inappropriate prescribing and health outcomes in elderly veteran outpatients. Ann Pharmacother. 1997;31(5):529–533.9161643
93 Schmader KE, Hanlon JT, Pieper CF, Sloan R, Ruby CM, Twersky J, . Effects of geriatric evaluation and management on adverse drug reactions and suboptimal prescribing in the frail elderly. Am J Med. 2004;116(6):394–401.15006588
94 Schmidt I, Claesson CB, Westerholm B, Nilsson LG, Svarstad BL. The impact of regular multidisciplinary team interventions on psychotropic prescribing in swedish nursing homes. J Am Geriatr Soc. 1998;46(1):77–82.9434669
95 Schmidt-Mende K, Andersen M, Wettermark B, Hasselstrom J. Educational intervention on medication reviews aiming to reduce acute healthcare consumption in elderly patients with potentially inappropriate medicines-a pragmatic open-label cluster-randomized controlled trial in primary care. Pharmacoepidemiol Drug Saf. 2017;26(11):1347–1356.28799226
96 Shim YW, Chua SS, Wong HC, Alwi S. Collaborative intervention between pharmacists and physicians on elderly patients: a randomized controlled trial. Ther Clin Risk Manag. 2018;14:1115–1125.29942134
97 Simon SR, Smith DH, Feldstein AC, Perrin N, Yang X, Zhou Y, . Computerized prescribing alerts and group academic detailing to reduce the use of potentially inappropriate medications in older people. J Am Geriatr Soc. 2006;54(6):963–968.16776793
98 Spinewine A, Swine C, Dhillon S, Lambert P, Nachega JB, Wilmott L, . Effect of a collaborative approach on the quality of prescribing for geriatric inpatients: A randomized, controlled trial. J Am Geriatr Soc. 2007;55(5):658–665.17493184
99 Stein CM, Griffin MR, Taylor JA, Pichert JW, Brandt KD, Ray WA. Educational program for nursing home physicians and staff to reduce use of non-steroidal anti-inflammatory drugs among nursing home residents: a randomized controlled trial. Med Care. 2001;39(5):436–445.11317092
100 Tamblyn R, Huang A, Perreault R, Jacques A, Roy D, Hanley J, . The medical office of the 21st century (MOXXI): effectiveness of computerized decision-making support in reducing inappropriate prescribing in primary care. CMAJ. 2003;169(6):549–556.12975221
101 Terrell KM, Perkins AJ, Dexter PR, Hui SL, Callahan CM, Miller DK. Computerized decision support to reduce potentially inappropriate prescribing to older emergency department patients: a randomized, controlled trial. J Am Geriatr Soc. 2009;57(8):1388–1394.19549022
102 Torisson G, Minthon L, Stavenow L, Londos E. Multidisciplinary intervention reducing readmissions in medical inpatients: A prospective, non-randomized study. Clin Interv Aging. 2013;8:1295–1304.24106422
103 Trivalle C, Cartier T, Verny C, Mathieu AM, Davrinche P, Agonstini H, . Identifying and preventing adverse drug events in elderly hospitalised patients: A randomised trial of a program to reduce adverse drug effects. J Nutr Health Aging. 2010;14(1):57–61.20082055
104 Tse W, Frisina PG, Halbig TD, Gracies JM, Liang L, Tarshish C, . The effects of withdrawal of dopaminergic medication in nursing home patients with advanced Parkinsonism. J Am Med Dir Assoc. 2008;9(9):670–675.18992700
105 Van Der Meer HG, Wouters H, Pont LG, Taxis K. Reducing the anticholinergic and sedative load in older patients on polypharmacy by pharmacist-led medication review: A randomised controlled trial. BMJ Open. 2018;8(7):e019042.
106 Van Der Spek K, Koopmans RT, Smalbrugge M, Nelissen-Vrancken MH, Wetzels RB, Smeets CH, . The effect of biannual medication reviews on the appropriateness of psychotropic drug use for neuropsychiatric symptoms in patients with dementia: a randomised controlled trial. Age Ageing. 2018;47(3):430–437.29432518
107 Weber V, White A, McIlvried R. An electronic medical record (EMR)-based intervention to reduce polypharmacy and falls in an ambulatory rural elderly population. J Gen Int Med. 2008;23(4):399–404.
108 Wehling M, Burkhardt H, Kuhn-Thiel A, Pazan F, Throm C, Weiss C, . VALFORTA: a randomised trial to validate the FORTA (Fit fOR The Aged) classification. Age Ageing. 2016;45(2):262–267.26786346
109 Willoch K, Blix HS, Pedersen-Bjergaard AM, Eek AK, Reikvam A. Handling drug-related problems in rehabilitation patients: a randomized study. Int J Clin Pharm. 2012;34(2):382–388.22388601
110 Zermansky AG, Petty DR, Raynor DK, Freemantle N, Vail A, Lowe CJ. Randomised controlled trial of clinical medication review by a pharmacist of elderly patients receiving repeat prescriptions in general practice. BMJ. 2001;323(7325):1340–1343.11739221
111 Wouters H, Scheper J, Koning H, Brouwer C, Twisk JW, Van Der Meer H, . Discontinuing inappropriate medication use in nursing home residents :a cluster randomized controlled trial. Ann Int Med. 2017;167(9):609–617.29052691
112 Jager C, Freund T, Steinhauser J, Stock C, Krisam J, Kaufmann-Kolle P, . Impact of a tailored program on the implementation of evidence-based recommendations for multimorbid patients with polypharmacy in primary care practices-results of a cluster-randomized controlled trial. Implement Sci. 2017;12(1):8.28086976
113 Rognstad S, Brekke M, Mdala I, Fetveit A, Gjelstad S, Straand J. Characteristics of GPs responding to an educational intervention to minimise inappropriate prescriptions: subgroup analyses of the Rx-PAD study. BJGP Open. 2018;2(1).
114 Touchette DR, Masica AL, Dolor RJ, Schumock GT, Choi YK, Kim Y, . Safety-focused medication therapy management: a randomized controlled trial. J Am Pharm Assoc. 2012;52(5):603–612.
115 Tannenbaum C, Martin P, Tamblyn R, Benedetti A, Ahmed S. Reduction of inappropriate benzodiazepine prescriptions among older adults through direct patient education: the EMPOWER cluster randomized trial. JAMA Int Med. 2014;174(6):890–898.
116 Bryant LJM, Coster G, Gamble GD, McCormick RN. The General Practitioner-Pharmacist Collaboration (GPPC) study: a randomised controlled trial of clinical medication reviews in community pharmacy. Int J Pharm Practice. 2011;19(2):94–105.
117 Gnjidic D, Le Couteur DG, Abernethy DR, Hilmer SN. A pilot randomized clinical trial utilizing the drug burden index to reduce exposure to anticholinergic and sedative medications in older people. Ann Pharmacother. 2010;44(11):1725–1732.20876826
118 Lenander C, Elfsson B, Danielsson B, Midlov P, Hasselstrom J. Effects of a pharmacist-led structured medication review in primary care on drug-related problems and hospital admission rates: a randomized controlled trial. Scand J Prim Health Care. 2014;32(4):180–186.25347723
119 Richmond S, Morton V, Cross B, Chi Kei Wong I, Russell I, Philips Z, . Effectiveness of shared pharmaceutical care for older patients: RESPECT trial findings. Br J Gen Pract. 2010;60(570):14–20.
120 Steinman MA, Low M, Balicer RD, Shadmi E. Impact of a nurse-based intervention on medication outcomes in vulnerable older adults. BMC Geriatr. 2018;18(1):207.30189846
121 Bernsten C, Bjorkman I, Caramona M, Crealey G, Frokjaer B, Grundberger E, . Improving the well-being of elderly patients via community pharmacy-based provision of pharmaceutical care. A multicentre study in seven European countries. Drugs Aging. 2001;18(1):63–67.11232739
122 Brooker DJ, Latham I, Evans SC, Jacobson N, Perry W, Bray J, . FITS into practice: translating research into practice in reducing the use of anti-psychotic medication for people with dementia living in care homes. Aging Ment Health. 2016;20(7):709–718.26167720
123 Cheek J, Gilbert A, Ballantyne A, Penhall R. Factors influencing the implementation of quality use of medicines in residential aged care. Drugs Aging. 2004;21(12):813–824.15382960
124 Desveaux L, Saragosa, M., Rogers, J., Bevan, L. Improving the appropriateness of antipsychotic prescribing in nursing homes: a mixed-methods process evaluation of an academic detailing intervention. Implement Sci. 2017;12:71.28549480
125 Kempen TGH, Gillespie U, Fardborg M, McIntosh J, Mair A, Stewart D. A case study of the implementation and sustainability of medication reviews in older patients by clinical pharmacists. Res Social Adm Pharm. 2018;19:19.
126 Kuntz J, Kouch L, Christian D, Peterson PL, Gruss I. Barriers and facilitators to the deprescribing of nonbenzodiazepine sedative medications among Older Adults. Perm J. 2018;22:17–157.
127 Latham I, Brooker D. Reducing anti-psychotic prescribing for care home residents with dementia. Nurse Prescr. 2017;15(10):504–511.
128 Ranson C, Jamieson T, Humphreys M, De Biase S, Dyson J, McGeorge M,. Understanding cognitive barriers to safer prescribing for frail patients. Clin Pharm. 2018;10(5).
129 Vandenberg AE, Echt KV, Kemp L, McGwin G, Perkins MM, Mirk AK. Academic detailing with provider audit and feedback improve prescribing quality for older Veterans. J Am Geriatr Soc. 2018;66(3):621–627.29532466
130 Jager C, Steinhauser J, Freund T, Kuse S, Szecsenyi J, Wensing M. A tailored programme to implement recommendations for multimorbid patients with polypharmacy in primary care practices-process evaluation of a cluster randomized trial. Implement Sci. 2017;12(1):31.28264693
131 Vandenberg A, Vaughan C, Stevens M, Hastings SN, Powers J, Markland A, . Improving geriatric prescribing in the ED: a qualitative study of facilitators and barriers to clinical decision support tool use. Int J Qual Health Care. 2017;29(1):117–123.27852639
132 Page AT, Clifford RM, Potter K, Schwartz D, Etherton-Beer CD. The feasibility and effect of deprescribing in older adults on mortality and health: A systematic review and meta-analysis. BrJ Clin Pharmacol. 2016:82:583–623.27077231
133 Johansson T, Abuzahra ME, Keller S, Mann E, Faller B, Sommerauer C, . Impact of strategies to reduce polypharmacy on clinically relevant endpoints: a systematic review and meta-analysis. Br J Clin Pharmacol. 2016;82:532–548.27059768
134 Rankin A, Cadogan CA, Patterson SM, Kerse N, Cardwell CR, Bradley MC, . Interventions to improve the appropriate use of polypharmacy for older people. Cochrane Database of Systematic Reviews. 2018(9) No.: CD008165.30175841
135 Tasai S, Kumpat N, Dilokthornsakul P, Chaiyakunapruk N, Saini B, Dhippayom T. Impact of medication reviews delivered by community pharmacist to elderly patients on polypharmacy: a meta-analysis of randomized controlled trials. J Patient Saf. 2019;00(00):1–9.
136 Linsky A, Simon SR, Bokhour B. Patient perceptions of proactive medication discontinuation. Patient Educ Couns. 2015;98(2):220–225.25435516
137 Reeve E, To J, Hendrix I, Shakib S, Roberts MS, Wiese MD. Patient barriers to and enablers of deprescribing: a systematic review. Drugs Aging. 2013;30(10):793–807.23912674
138 Linsky A, Simon SR, Marcello TB, Bokhour B. Clinical provider perceptions of proactive medication discontinuation. Am J Manag Care. 2015;21(4):277–283.26014466
139 Anderson K, Stowasser D, Freeman C, Scott I. Prescriber barriers and enablers to minimising potentially inappropriate medications in adults: a systematic review and thematic synthesis. BMJ Open. 2014;4(12):e006544.
140 Reeve E, Moriarty F, Nahas R, Turner JP, Kouladjian O’Donnel L, Hilmer SN. A narrative review of the safety concerns of deprescribing in older adults and strategies to mitigate potential harms. Expert Opin Drug Saf. 2018;17(1):39–49.29072544