# Acknowledgments

This topic was developed in response to a nomination by Kenneth Boockvar, MD, MS, for the purpose of identifying deprescribing practices, tools, and products that have the greatest potential to be implemented in the Veterans Health Administration. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Kenneth Boockvar, MD, MS
  Center for Medication Safety in Aging
- Marianne Shaughnessy, PhD, CRNP
  Office of Geriatrics and Extended Care
- Ilse Wiechers, MD, MPP, MHS
  National Program Director-Psychotropic Drug Safety Initiative

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Mary Goldstein, MD
  VA Palo Alto Health Care System
  Stanford University Department of Medicine
- Eric Hermes, MD
  VA Connecticut Healthcare System
  Yale University School of Medicine
- Jean Kutner, MD, MPH/MSPH
  University of Colorado School of Medicine
- Zachary Marcum, PharmD, MS, PhD
  University of Washington School of Pharmacy
- Michael Steinman, MD
  University of California San Francisco
  San Francisco VA Medical Center

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.