# Summary and Discussion

This systematic review determined the effectiveness of deprescribing interventions designed to mitigate the adverse effects of polypharmacy and use of inappropriate medications in older community-dwelling Veterans. The results of this review are intended to inform the development and implementation of deprescribing initiatives within VA. We focus our discussion on the most commonly reported primary outcomes (falls, hospital admissions, health-related quality of life, all-cause mortality) and reduction in PIMs, a secondary outcome judged important to our nominators, technical panel members, and this review team.

Our 2 key questions were:

KQ1 What is the effectiveness, comparative effectiveness, and harms of deprescribing interventions among adults age 65 and older?
  KQ1a What are the identified elements/components that contribute the most to the effectiveness of deprescribing interventions?
  KQ1b Do the effectiveness, comparative effectiveness, and harms of deprescribing interventions vary by patient population, provider factors, or setting?
KQ2 What are the identified facilitators and barriers that impact the implementation of deprescribing interventions within large-scale health systems such as VA?

## Summary of Evidence and Certainty of Evidence by Key Question

### Key Question 1

We identified 38 trials (12 RCTs, 26 cluster RCTs) in community and primary care settings that met our inclusion criteria and were rated as low or medium risk of bias. We divided the trials into 4 intervention categories: comprehensive medication review (CMR) (k=21), education (k=10), computer-based (k=4), and hybrid/other (k=3). Almost all trials compared the intervention to a usual care control.

#### Key Messages

- [underlined: Comprehensive Medication Review] may reduce all-cause mortality (low certainty of evidence), potentially inappropriate medications, and costs compared to usual care.
- [underlined: Education (Provider and Patient Directed)]
  ○ A direct-to-consumer patient engagement program with targeted educational material provided directly to patients may reduce PIMs.
  ○ Provider education without feedback had no significant effect on outcomes; however, when coupled with patient-specific feedback to the provider, it may reduce PIMs.
- [underlined: Computer Decision Support], such as with electronic health record alerts and other clinical decision support systems, may reduce PIMs.
- [underlined: Hybrid/Other Interventions] may reduce falls and PIMs.
- There was no evidence of harms (adverse drug withdrawal events, worsening of medical conditions, or increased mortality, hospitalizations, or major adverse cardiovascular events) associated with any of the deprescribing interventions.
- No studies addressed the comparative effectiveness of the deprescribing interventions either within or across categories.
- Most studies were not designed to assess mortality, hospitalizations, delirium, falls, or major adverse cardiovascular events and no studies reported on biomarker measures such as glycemic or blood pressure control.

##### Comprehensive Medication Review (CMR), k=21

The CMR interventions were generally led by a pharmacist and included chart review, patient interview, and provider consultation, culminating in recommendations for medication regimen changes to a physician. Nine trials included a follow-up intervention with patients to reinforce the recommendations, such as home-care visits by nurses or telephone calls by pharmacists. We judged the risk of bias to be low in 5 trials and medium in 16. Outcomes were reported on about 8000 patients, with study sample sizes ranging from 25 to 1403.

All-cause Mortality: Pooled data on 3875 enrollees in 11 trials indicate that CMR may reduce all-cause mortality by about 20% (OR 0.79, 95% CI: 0.58 to 1.08, I^2^ =0). Certainty of evidence was low.

Falls: Three of 4 studies reporting falls found no difference between the CMR intervention and the control group. The studies were not considered suitable for pooling. Certainty of evidence was low.

Hospitalizations: None of the 12 trials reporting hospitalizations found an intervention effect. Results of the 6 studies suitable for pooling showed that compared to control, the CMR interventions had no effect on number of participants with 1 or more unplanned hospital admission during follow-up (RR 1.07, 95% CI: 0.92 to 1.26, I^2^=12%). Certainty of evidence was moderate.

Health-related Quality of Life: Nine of the 11 trials that reported a quality of life outcome found no differences between the CMR and the control intervention. The studies were not considered suitable for pooling. Certainty of evidence was low.

Medication Changes: Nineteen trials reported at least 1 medication change measure: 12 reported reduction in potentially inappropriate medication use; 2 in drug-related problems, and 5 in total number of medications. Twelve of the 19 trials (63%) found that, compared to control, the CMR intervention resulted in a reduction in 1 or more of these outcomes. The studies were not considered suitable for pooling. In the 5 trials in which standardized mean differences could be calculated, the intervention effect was moderate in 2, small in 1, and less than small in 2.

There were no differences between the negative and positive studies with respect to length of follow-up, risk of bias, enrollee demographics, or country. However, in 5 of the 12 positive studies (42%), the protocol included additional follow-up with the patient after the initial CMR. Only 2 of the 7 negative studies (29%) included such follow-up.

Health Care Costs: Of the 7 studies reporting a cost outcome, 3 reported no difference between intervention and control groups (2 of these studies reported medication costs only and 1 reported a cost-utility analysis); 1 reported a cost benefit analysis suggesting that the CMR intervention was cost-effective. The other 3 studies evaluated both medication costs and costs of implementing the CMR intervention: 1 reported no net difference in costs between intervention and control groups; 1 reported that costs increased in both intervention and control groups, but the net increase was smaller in the intervention group; and 1 reported that the costs decreased in both groups but the net decrease was larger in the intervention group.

##### Education Interventions, k=10

We identified 10 trials that evaluated the effect of educational interventions directed at either patients (k=1), providers (k=5), or both (k=4). The control groups were assigned either usual care (k=8) or a sham intervention (ie, targeting drugs that were not of interest, k=2). We judged the risk of bias to be low in half the trials and medium in the other half. Outcomes were reported on a total of 2424 patients in the 7 smaller trials and on 252,684 in the 3 larger trials.

All-cause mortality: All-cause mortality was reported in 5 trials (n=121,124). None of the trials reported a difference between intervention and control groups. The data were not suitable for pooling. Certainty of evidence was moderate.

Falls: In the only trial that reported falls, there was no difference between intervention and control groups. Certainty of evidence was low.

Hospitalizations: Three of the 4 trials that reported hospitalizations found no difference between intervention and control groups. The data were not considered suitable for pooling. Certainty of evidence was moderate.

Health-related Quality of Life: The 2 trials that reported a quality of life measure found no difference between intervention and control groups. Certainty of evidence was low.

Medication Changes: Nine trials reported potentially inappropriate medications (PIMs). Six found that compared to control, the intervention was associated with fewer PIMs at the end of the study. The interventions used in these 6 studies were: a direct-to-consumer patient engagement program with targeted educational material mailed directly to patients (k=2 low risk of bias trials); provider education plus feedback (k=2, 1 low, 1 med risk of bias); and patient education with provider education plus feedback (k=2, 1 low, 1 med risk of bias). The 2 studies testing provider education alone did not report an effect on PIMs.

##### Computer Decision Support Interventions k=4

We identified 4 trials that evaluated the effect of a computer-based intervention. Samples sizes ranged from 128 to 59,680 patients and study periods ranged from 90 days to 13 months. All 4 trials were considered medium risk of bias. In all 4 trials reduction in potentially inappropriate prescriptions was the only outcome reported.

Two of the 4 trials reported that the intervention resulted in fewer PIMs. The negative studies may have been underpowered to detect a difference; both had shorter duration of follow-up (13 weeks and 16 weeks) than the positive studies (12 and 13 months).

##### Hybrid/Other Interventions k=3

We classified 3 trials as hybrid because they included interventions from at least 2 of the 3 other categories. In all 3 trials the comparison group was usual care. A total of 1683 patients were followed for 12 months. One trial was considered low risk of bias and 2 were considered medium risk. All 3 studies focused on psychotropic medications.

All-cause Mortality: All-cause mortality was reported in 1 trial: there were 2 deaths in both the intervention and control groups.

Falls: The only trial that evaluated falls found that at 12 months of follow-up, the intervention group had significantly fewer falls, fall-related injuries, and falls requiring medical attention. The multicomponent intervention in this medium risk of bias Australian trial included provider education and feedback, comprehensive medication review, and physician reimbursement.

Health-related Quality of Life: The 2 trials that evaluated quality of life found no differences between intervention and control groups.

Medication Changes: All 3 trials reported medication regimen improvements in the intervention compared with the control groups.

### KQ1a What are the identified elements/components that contribute the most to the effectiveness of deprescribing interventions?

We did not identify any studies that explicitly addressed this question. However, as described above, it appears that patient-specific performance feedback to providers improves the effectiveness of educational interventions and that follow-up interventions such as phone calls or clinic visits with patients may improve the effectiveness of comprehensive medication reviews.

### KQ1b Do the effectiveness, comparative effectiveness, and harms of deprescribing interventions vary by patient population, provider factors, or setting?

The included studies were very similar with respect to patient population (older adults taking multiple medications and living in the community) and setting (primary care clinics). Only 1 study explicitly analyzed the effect of provider factors on intervention effectiveness. This Norwegian study of a provider education and feedback intervention reported that physician factors associated with prescribing improvements included age 57–68, advanced training in primary care, and working in solo practices.

Eleven studies reported the effect of the intervention on use of psychotropic medications. None of the CMR studies (k=3) or the hybrid/other studies (k=3) found an intervention effect, but 4 of 5 trials of an educational intervention reported a reduction in psychotropic use at follow-up.

Fourteen of the 21 trials that compared a CMR intervention to usual care reported that the intervention resulted in at least 1 favorable outcome. Compared to the 7 trials that did not report an intervention effect, these trials were more likely to have follow-up times of less than 1 year (64% vs 43%) and to have included an additional intervention (eg, patient call or visit) during follow-up (50% vs 14%). Otherwise there did not appear to be any systematic differences between the positive and negative studies with respect to country, sample size, risk of bias, or characteristics of the enrollees or the interventions.

### Recent Systematic Reviews

None of the systematic reviews we identified used the same inclusion/exclusion criteria or reported results by the intervention categories that we used. Nevertheless, most of these reviews reported results generally consistent with our findings.

All-cause Mortality: A recent systematic review of observational and experimental studies (k=132) evaluated the effect of any type of deprescribing intervention in people age ≥65 in any setting. The review’s primary outcome was all-cause mortality. Deprescribing was associated with decreased mortality in both randomized (OR 0.82, 95% CI: 0.61 to 1.11) and non-randomized studies (OR 0.32, 95% CI: 0.17 to 0.60). Interventions that were patient-specific were more effective than generalized educational programs.^132^ Another review of RCTs and CCTs that evaluated any deprescribing intervention in any setting reported an OR of 1.02 (95% CI: 0.84 to 1.23).^133^ The effect size and confidence intervals from these reviews are very similar to what we found in our CMR trials.

Falls: In the systematic review described above, Page et al reported that deprescribing did not have a significant effect on risk of 1 or more falls (OR 0.65, 95% CI: 0.40 to 1.05).^132^ This was based on pooled results from 5 RCTs; half the participants were nursing home residents.

Hospitalizations: At least 3 other systematic reviews reported the effect of deprescribing interventions on hospital admissions. A Cochrane review that included several different study designs (trials, controlled before-after, and interrupted time-series) concluded, based on data from 12 studies, that “pharmaceutical care [ie, CMR] may make little or no difference in hospital admissions”.^134^ A systematic review that included RCTs and CCTs of any deprescribing intervention in any setting was unable to pool hospitalization outcomes; most of the identified studies found no intervention effect.^133^

A very recent systematic review of 4 RCTs that evaluated community pharmacist-led medication review programs reported that the intervention had a significant impact on emergency department visits (RR 0.68, 95% CI: 0.48 to 0.96) and may have led to fewer hospitalizations (RR 0.88, 95% CI: 0.78 to 1.00). Only 1 of these 4 studies was included in the present review.^135^

Health-related Quality of Life: The Cochrane review concluded that “pharmaceutical care may make little or no difference” in quality of life based on 12 studies that were not deemed suitable for pooling.^134^ The review of the 4 RCTs of community pharmacist-led medication review programs found mixed results among the 3 trials that reported quality of life outcomes.^135^ Page et al reported that only 1 of 18 trials reported an intervention effect on quality of life.^132^

Medication Changes: The Cochrane review reported number of enrollees on 1 or more PIMs at the end of the study (k=11) and concluded that subjects in the deprescribing interventions group were less likely to be on a PIM than the control group (RR 0.79 95% CI: 0.61 to 1.02, I^2^=85%).^134^ Page et al reported pooled results from 3 studies with 839 subjects; compared to the control conditions, deprescribing reduced the number of inappropriate medications (mean difference −0.49, 95% CI: −0.7 to −0.28).^132^

### Key Question 2 What are the identified facilitators and barriers that impact the implementation of deprescribing interventions within large-scale health systems such as VA?

We included 9 studies that assessed barriers and facilitators of implementing a deprescribing intervention in a large health care system as part of the implementation process. Five of the studies were from community/primary care settings, 3 from nursing homes, and 1 from an emergency department. Interventions included CMR (6 studies), education (2 studies), and computer decision support (1 study). In most studies, fewer than 25 prescribers or others involved with the intervention were interviewed following implementation. Two studies also sought input from either patients or nursing home residents.

#### Key Messages

- Few studies assessed barriers or facilitators of implementation meeting eligibility for inclusion in our review. The perspective of patients/nursing home residents or family members was only assessed in 2 of 9 studies.
- Barriers and facilitators of implementation of CMR, educational, and computer decision support deprescribing interventions included patient (eg, concerns about safety of alternative medication regimens, reluctance to give up medications), prescriber (eg, lack of knowledge, not believing in need for CMR), and system factors (eg, lack of institutional support and resources, inadequate time).

Although we found few studies conducted in the context of a specific deprescribing intervention, several recent papers have reported on barriers to and facilitators of deprescribing. To determine patient perspectives on deprescribing, interviews and focus groups were conducted with 27 US Veterans.^136^ Few of the participants had discussed discontinuation of medications with their provider. Patients expressed conflicting views of medication. They would like to take fewer medications but were concerned about possible adverse consequences if the medications were discontinued. They also noted the importance of their relationship with their provider. Many commented that they trust their provider and rely on his/her expertise while others expressed a desire for more information about their medications (why they were taking them, possible harms) and more involvement in decision-making.

A 2013 systematic review of 21 studies identified patient barriers and facilitators.^137^ Patients who had noted an improvement in their condition when they started a medication (or hoped for an improvement in the future) were reluctant to discontinue the medication. Conversely, if they felt the medication was no longer needed, perceived a lack of effectiveness, were concerned about side effects or addiction, or mistrusted the initial prescriber, they were more accepting of the possibility of deprescribing. Patients expressed concern over insufficient provider time for discussion and support necessary to discontinue a medication but were more accepting of deprescribing if viewed as a “test” with support from their provider. Some patients felt pressured by family and providers to take the medication initially; others reported prior negative experiences with ceasing medications. The availability of new evidence about medications (particularly potential harms) and support of physicians and family members were facilitators of deprescribing. Patients also reported disliking medications – inconvenient, expensive, unnatural – as a facilitator of deprescribing.

Provider perspectives were identified in interviews with VA physicians, nurse practitioners, and pharmacists.^138^ Participants (n=20) identified factors that influence their decisions about discontinuing medications. Responses were categorized as medication factors, patient factors, provider factors, and system factors. Medication factors included issues related to the patient’s current medication regimen (eg, number of doses, duplicate medications) and uncertainty about indication. Patient factors included complexity of comorbid conditions; age; perception of patient’s knowledge, beliefs, and preferences; and uncertainty about adherence. Professional identify was also a factor in decision-making. Providers felt responsible for making prescribing decisions and caring for their patients although their definitions of polypharmacy varied. Included under system factors were concerns about patients receiving care from multiple providers, the work load associated with deprescribing (additional communication, monitoring), and external directives or policies that focus on achieving target goals regardless of patient age or preferences, inaccuracies in medical records, and concern about the number of computer generated reminders and alerts.

A 2014 systematic review^139^ focused on provider perspectives from 21 studies (3 of which were also included in the patient-centered review by Reeve et al^137^). Most of the 21 included primary care providers caring for older, community-based patients. Lack of awareness of the appropriateness of their prescribing behavior was an identified barrier along with inertia (ie, failure to act despite awareness). Providers noted potential negative outcomes, belief that drugs are effective with few adverse effects, potential increased workload, and concerns about deprescribing of medications prescribed by another provider. Some prescribers believed they lacked the knowledge to address potentially inappropriate medication use or they believed their prescribing was based on guideline recommendations and were hesitant to deviate from those recommendations. Targeted training with more information about potential benefits and harms of deprescribing were identified as factors to overcome those barriers. Some providers cited barriers associated with feasibility including patient resistance to change, limited time, limited availability of treatment options, respect for the prescribing decisions of colleagues, and the need to meet quality metrics.

## Research Gaps/Future Research

The most glaring gap is the absence of comparative effectiveness trials. This is particularly important since the literature to date does not conclusively identify 1 deprescribing approach that is clearly superior to others. Since the VA Academic Detailing Service is planning to introduce VIONE, a medication management tool to reduce polypharmacy risk, this might be a good opportunity to acquire comparative effectiveness data. Consultation with implementation and quality improvement evaluation experts within VA Health Services Research & Development to design a robust roll-out plan that varies key conditions across different sites would likely yield important insights into best practices.

Other gaps that could be addressed by future research include:

- Absence of standardized definitions for deprescribing, components of the interventions, and how key outcomes are measured making it difficult to compare studies;
- A paucity of contemporary studies evaluating the role of the electronic medical health record in deprescribing efforts and its effects on patient-centered outcomes (eg, quality of life, falls, hospitalizations);
- Few process evaluations accompanying clinical trials; implementation studies would provide guidance on how to incorporate deprescribing interventions into health care settings;
- Few studies were conducted in the US or in VA, and the preponderance of patients enrolled were female; of the 38 trials included, only 10 were conducted in the US, of which only 2 were in VA;
- Little data to support which care team members (eg, physician, nurse, pharmacist) can and should be responsible for different aspects of the deprescribing process;
- Insufficient focus on important patient-centered outcomes such as quality of life, falls, major adverse cardiovascular events, and cognitive function, as well as biomarker measures such as glycemic or blood pressure control likely important to patients, providers, and health systems when considering medication deprescribing; and
- Lack of data from RCTs on adverse effects of deprescribing; more information on this topic can be found in reviews that were not limited to clinical trials.^140^

## Applicability of Findings to VA

Key Question 1: As noted above, only 2 studies were conducted in VA, most were not conducted in the US, and the preponderance of participants were women. Nevertheless, our findings can, and should, inform efforts in VA to develop deprescribing interventions. Enrolled individuals were community-dwelling older adults with multiple chronic conditions and receiving care in primary care clinics or community settings. Interventions were varied in their components and strategies and typically consistent with, and likely applicable to, VA. As these initiatives are rolled out as pilot projects, concurrent process evaluations should be conducted to determine best practices for implementation within VA.

Importantly, we did not find that deprescribing interventions led to patient-related harms. Furthermore, a strong rationale can be made in future VA work to choose PIMs as an important and patient-centered outcome, based on strong observational data that: 1) exposure to multiple medications is associated with increased risk of negative outcomes, such as falls, cognitive impairment and other geriatric syndromes, hospitalizations, and death; 2) the number of medications a person is taking may be the single most important predictor of adverse drug effects; 3) about 50% of older adults are taking 1 or more potentially inappropriate medications (PIMs), including those without a clear indication, duplicative medications, and medications known to pose risks in the elderly; and 4) costs and burden increase with medication number.

Evidence Map: Only 1 study included in the evidence map of studies in settings other than community/primary care, a study of a CMR intervention in hospital setting, was conducted in VA. Only 9 of the 48 studies were from the US and in only 3 of the 48 studies included populations of greater than 50% males.

Key Question 2: Our review of barriers to and facilitators of implementation of deprescribing interventions was limited to studies in large health care systems. We included 2 studies within VA – 1 in primary care and 1 in the emergency department. The findings from VA were similar to those in other health care systems, with barriers including time constraints, availability of clinical pharmacists, and concerns about loss of prescriber autonomy and quality of the information provided. Facilitators included perceived ability to improve prescribing safety and the potential for provision of information and training.

## Conclusions

Several options for deprescribing interventions may reduce the burden of polypharmacy and PIMs in community-dwelling older adults. CMR, the intervention most extensively evaluated, may reduce all-cause mortality, potentially inappropriate medication use, and costs. CMR might be feasible to implement, given the extensive presence of pharmaceutical expertise already embedded in ambulatory care clinics in VA. In designing a program, consideration should be given to incorporating a plan for follow-up contact with patients after the initial CMR. Implementing CMR in a research context or as part of a quality improvement project would increase the evidence base from VA settings.

Educational interventions, which reduced PIMs in most trials, are also worth exploring for implementation. Of particular interest are interventions that can be implemented at a system-level and that include a direct-to-consumer patient engagement component. Provider education with performance feedback may be useful. Provider education-only interventions are not effective.

Computer decision support interventions are a promising area for further research but are not ready to be implemented on a system-wide basis.

Overcoming describing barriers and enhancing facilitators could aide in implementation of optimal deprescribing practices and improve health care quality and value.