# Results

## Literature Flow

From the overall literature search (Key Questions 1 and 2), we identified 2,049 records after removing duplicates (Figure 2). Of those, 1,773 were excluded at the abstract level leaving 276 articles for full-text review. Two additional articles were identified from a recent systematic review. We excluded 170 articles and included 102 representing 86 trials.^14–115^ An additional 6 trials met eligibility criteria but were rated high risk of bias and not included in analyses.^116–121^

For the focused search for barriers and facilitators of implementation, we re-reviewed 30 references identified in the overall search along with citations from the focused search resulting in a total of 1,325 records (Figure 3). After excluding 1,222 at the abstract level, we did a full-text review of 103 articles. We included 9 studies reported in 10 papers.^122–131^

Figure 2 Literature Flow Chart – Key Question 1

Figure 3 Literature Flow Chart – Key Question 2

## Key Question 1 What are the effectiveness, comparative effectiveness, and harms of deprescribing interventions among adults age 65 and older?

We focus our review of effectiveness, comparative effectiveness, and harms on studies conducted in community or primary care settings. An evidence map summarizing studies from nursing home, hospital, emergency department, and palliative care settings is presented in Appendix C.

We identified 44 trials in 53 papers that met our inclusion criteria for KQ1. Six of these were rated high risk of bias and were not included in the analyses. Of the remaining 38, 12 were RCTs and 26 were CRCTs. Included studies were very similar with respect to patient population (older adults taking multiple medications and living in the community) and setting (primary care clinics). Most interventions focused on general deprescribing though some studies targeted particular medication classes (eg, benzodiazepines) or specific goals (eg, falls reduction). We found considerable variation in description of medication changes and reporting of outcomes.

Our primary outcomes were quality of life/ functional status, all-cause mortality, hospitalizations, falls, adverse drug withdrawal events (ADWE), major adverse cardiovascular events, and delirium. Secondary outcomes included total number of medications discontinued, number of medications with dosage decreased, number of potentially inappropriate medications (PIMs) discontinued, number of medications added or substituted, adherence to medications, types of medications discontinued, medication burden, and cost. We classified interventions into the following categories: Comprehensive Medication Review (CMR), Education (Provider or Patient Directed), Computer Decision Support, and Hybrid/Other. In this narrative summary, we focus on frequently reported outcomes; information about other outcomes is presented in Appendix D.

### Key Messages

- [underlined: Comprehensive Medication Review] may reduce all-cause mortality (low certainty of evidence), potentially inappropriate medications, and costs compared to usual care.
- [underlined: Education (Provider or Patient Directed)]
  ○ A direct-to-consumer patient engagement program with targeted educational material provided directly to patients may reduce PIMs.
  ○ Provider education without feedback had no significant effect on outcomes; however, when coupled with patient-specific feedback to the provider, it may reduce PIMs.
- [underlined: Computer Decision Support], such as with electronic health record alerts and other clinical decision support systems, may reduce PIMs.
- [underlined: Hybrid/Other Interventions] may reduce falls and PIMs.
- There was no evidence of harms (adverse drug withdrawal events, worsening of medical conditions, or increased mortality, hospitalizations, or major adverse cardiovascular events) associated with any of the deprescribing interventions.
- No studies addressed the comparative effectiveness of the deprescribing interventions either within or across categories.
- Most studies were not designed to assess mortality, hospitalizations, delirium, falls, or major adverse cardiovascular events, and no studies reported on biomarker measures such as glycemic or blood pressure control.

### Comprehensive Medication Review (CMR) (k=21)

#### Summary

Comprehensive medication review (CMR) programs may reduce all-cause mortality, potentially inappropriate medications, and health care costs. The trials either did not report or did not significantly improve health related quality of life, or reduce falls, MACE, delirium, hospitalizations, or acute care visits. No adverse drug withdrawal events were reported.

Fourteen of the 21 trials that compared a CMR intervention to usual care reported that the intervention resulted in at least 1 favorable outcome. Compared to the 7 trials that did not report an intervention effect, these trials were more likely to have follow-up times of less than 1 year (64% vs 43%) and to have included an additional intervention (eg, patient call or visit) during follow-up (50% vs 14%). Otherwise there did not appear to be any systematic differences between the positive and negative studies with respect to country, sample size, risk of bias, or characteristics of the enrollees or the interventions.

#### Overview of Studies

Twenty-one trials evaluated the effect of CMR compared to a control group, most often usual care.^14,20,24,25,34,46,47,50,53,54,56,60,62,63,67,70–73,92,96,105,107,110,114^ For the most part, the CMR interventions were led by a pharmacist and included a chart review, patient interview, and provider consultation, culminating in recommendations for medication regimen changes to a physician. Nine studies also included a follow-up intervention with patients to reinforce the recommendations, such as home-care visits by nurses or telephone calls by pharmacists. Six trials were conducted in the US, 1 in Canada, 1 in Malaysia, and 13 in Europe. Demographic characteristics of the enrolled patients are shown in Appendix D Table 1. We judged the risk of bias to be low in 5 trials and medium in 16 (Appendix D, Table 2). Outcomes were reported on about 8700 patients, with study sample sizes ranging from 25 to 1403.

#### Primary Outcomes

The primary outcomes reported were all-cause mortality, falls, hospitalizations and health-related quality of life/functional status/patient satisfaction metrics (Appendix D, Tables 3–5).

All-cause mortality: All-cause mortality was reported in 11 RCTs enrolling 3875 patients with follow-up ranging from 1–12 months. Compared to usual care, CMR resulted in a 21% relative risk reduction (OR 0.79, 95% CI: 0.58 to 1.08, I^2^=0) corresponding to a <1 percentage point absolute reduction (95% CI: −1.9 to 0.4) in all-cause mortality (Figure 4). Results were not statistically significant, perhaps due to the low number of events.

Figure 4 All-cause Mortality – CMR Studies

I^2^ = 0%

* These participants who died were reported in the study flow chart but were not included in the analyses. An unspecified number of participants also died but were included in the analyses.

† Intervention arms combined

Falls: Four trials reported fall outcomes. Two were specifically designed to assess falls.^20,107^ Only 1 study found a difference between the intervention and control groups; this study enrolled 620 adults >age 70 from a healthcare system in Pennsylvania and focused on medications that might increase the risk of falls. The intervention group had a 62% decrease in fall-related diagnoses during the 1-year study (OR 0.38, P<.01, CI not reported) despite no difference between groups in total number of medications or number of psychoactive medications at follow-up.^107^

Results from the other 3 trials are summarized in Figure 5. In the IMPROveFALL trial that enrolled 612 older adults who had visited an emergency room because of a fall, there was no difference between intervention and control groups at 12 months in either the number of falls (37% vs 34%; absolute risk difference 4%, 95% CI: −4 to 12), number of Fall-Risk-Increasing-Drugs, or the number of falls requiring medical attention.^20^

There was no difference in incidence of falls in the other 2 trials, neither of which had designated falls as the primary outcome and both of which had very short lengths of follow-up. One trial enrolled 259 participants and followed them for 6 to 12 weeks.^67^ The second was designed to decrease the anticholinergic sedative load in 157 older adults. After 3 months of follow-up there was no difference between the 2 groups in the number of falls.^105^

Figure 5 Absolute Risk Differences in Falls – CMR Studies

Hospitalizations: Hospitalizations over a wide range of follow-up durations were reported in 12 studies with a combined enrollment of 5672 participants. None of these studies reported a difference between the intervention and control groups with respect to number of participants with 1 or more hospitalizations during follow-up.^24,25,46,47,50,54,56,60,62,63,71,72,92,105,110,114^ In the 6 RCTs that could be pooled, 20.4% of people in the deprescribing group were hospitalized versus 19.8% in usual care for an absolute risk difference of 0.6% (95% CI: −2.3 to 3.5) (Figure 6). The remaining 6 studies could not be included in the pooled analysis due to the varying definitions of hospitalization,^46,50,54,62,63,71^ or because outcomes were not reported separately for intervention and control groups.^47,56,92^

Figure 6 Hospitalizations Following Deprescribing – CMR Studies (RCTs)

I^2^ = 12%

* Data from 3–6 month follow-up with basic and enhanced CMR arms combined

Health-related Quality of Life, Functional Status, and Patient Satisfaction: Eleven studies reported quality of life.^20,24,25,47,50,53,54,60,62,63,70,71,73,92,105^ Three of these also reported functional status^47,71,92,105^ and 2 reported a patient satisfaction outcome.^47,71,92^

Health-related quality of life was measured in all 11 studies with either the EuroQual Quality of Life scale (EQ-5D) (N=5), the Short Form Health Survey (SF-12/36) (k=5), or both (k=1). Nine studies reported no difference between the intervention and control groups in health-related quality of life at study end. The IMPROveFALL trial reported an improvement in the intervention compared to control group on the EQ-5D score, although not on either of physical or mental health component scores of the SF-12.^20,80^ The conSIGUE trial reported improved quality of life in the intervention vs the control group on both the EQ-5D and EQ-5D visual analog scale (VAS) as shown in Figure 7.^50,62,63^

Three studies reported a variety of functional status measures other than the EQ-5D or the SF-12/36 component scores.^47,71,92,105^ None found any differences between intervention and control groups on any metric. Neither of the studies reporting a patient satisfaction score found any differences between intervention and control group.^47,71,92^

Figure 7 Standardized Mean Differences for Quality of Life – CMR Studies

#### Secondary Outcomes: Medication Changes

Nineteen studies reported at least 1 medication outcome. Outcomes included frequency of drug-related problems (k=3), reduction in total number of medications (k=10), and improvement in medication regimen appropriateness (k=12) (Appendix D, Tables 6 and7).

Reduction in Drug-related Problems (k=3): All trials reporting drug-related problems found that the CMR intervention was more effective than usual care.^54,56,114^ A Dutch trial enrolled 125 patients from community pharmacies and reported that at 6 months, the mean number of drug changes was higher in the intervention group compared with the wait-list group (2.2 vs 1.0, P=.02) and the number of drug-related problems leading to a recommendation for a change was lower in the intervention compared to the control group (29% reduction in drug-related problems in the intervention group vs 5% in the control group, P<.01).^56^

A trial in the UK that enrolled 332 people age ≥65 taking at least 4 medications reported that at 3 months, the intervention group had a higher percentage of resolved “pharmaceutical care issues” compared to control subjects (78.8% vs 39.3%, P<.0001).^54^

A US trial randomized 637 people age ≥65 with ≥3 chronic conditions and ≥6 prescription medications to either usual care, basic CMR including patient interview only, and enhanced CMR including a medical record synopsis and patient interview. At 3 months, the average number of drug-related problems in the enhanced CMR group was lower than in the basic CMR group (OR: 0.43, 95% CI: 0.37 to 0.49, P<.001).^114^

Reduction in Total Number of Medications (k=10): Six of the 10 trials that reported reduction in total number of medications found no difference between intervention and control groups.^14,46,47,71,73,92,107^ In 3 of the 4 trials reporting a difference, the mean difference was less than 1 medication and of uncertain clinical significance (Table 2).^24,25,60,110^ ^50,62,63^

Reduction in Potentially Inappropriate Medications (k=12): Twelve trials reported inappropriate medication use; 5 of these included the Medication Appropriateness Index (MAI; scores range from 0=completely appropriate prescription to 18=completely inappropriate prescription).^47,92^ Six trials found no difference between intervention and control groups.^14,20,46,71,73,105^ However, the study by Haag^46^ was very small and short term, the trial by Allard had a nearly 2-fold increase in the number of patients not being on a PIM,^14^ and the study by Boyé^20^ noted a decrease in the percentage of individuals on PIMs. Six other trials found significant reductions in PIMs, duplication medications, or MAI scores. Results are summarized in Table 3.

Table 2 Reduction in Total Number of Medications – CMR Studies

Author; Number enrolled; Length of follow-up | Findings
Allard, 2001^14^; n=266; 12 months | Difference in mean number (SD) of drugs prescribed baseline to follow-up: Intervention: 0.24 (2.15); Control :0.13 (1.67)
Campins, 2017, 2019^24,25^; n=503; 12 months | % of enrollees with 1 or more fewer medications at follow-up: 85% in intervention vs 75% in control group; OR:1.85, 95% CI: 1.17 to 2.9, P=.008
Haag, 2016^46^; n=25; 1 month | Intervention: median number of medications: 17 (IQR 12–20) at baseline to 18 (12–20) at follow-up; Control: 15.5 (13–18.5) to 17 (13–18) at follow-up
Hanlon, 1996, Schmader 1997^47,92^; n=208; 3, 12 months | Mean number of VA-prescribed medications at 12 months: Intervention: 6.9 (2.6), Control: 7.9 (3.3), P=.83
Jodar-Sanchez, 2015^50^; Malet-Larrea 2016, 2017^62,63^; n=1403; 6 months | Difference in mean number of prescribed medications in the intervention vs control group: - 0.21 drugs, 95% CI: −0.092 to −0.335, P=.001
Lenaghan, 2007^60^; n=136; 6 months | Difference in mean number of prescribed medications in the intervention vs control group: −0.87 drugs, 95% CI: −1.66 to −0.08, P=0.03
Muth, 2018^71^; n=505; 9 months | Adjusted mean difference in number of medications between 2 groups: 1.0 (1.0 to 1.1)
Olsson, 2012^73^; n=150; 12 months | Median number of drugs at baseline/follow-up: Control: 8.0/9.0; Intervention 1: 10.0/11.0; Intervention 2: 10.0/10.0
Weber, 2008^107^; n=620; 15 months | Mean number of medications from baseline to end of study: Intervention 7.65 to 7.88; Control: 7.46 to 7.62
Zermansky, 2001^110^; n=1188; 12 months | Increase in number of medications in intervention vs control groups: 0.2 vs 0.4, P=.01

CI=confidence interval; SD=standard deviation; IQR=interquartile range; OR=odds ratio; VA=Veterans Affairs

Table 3 Potentially Inappropriate Medications – CMR Studies

Author; Number enrolled; Length of follow-up | Findings
Allard, 2001^14^; n=266; 12 months | Reduction in PIMs/patient: 0.24 (Intervention) vs 0.15 (Control), P=.13; odds of NOT being on a PIM at study’s end in the intervention group was 1.83 (95% CI: 0.94 to 3.57)
Boyé 2017,^20^ 2017; n=612; 12 months | % using ≥ 3 fall risk increasing medications went from 72% to 75% from baseline to 1 year in control group and stayed at 70% in intervention group; % with decreased PIMs: 37% (Intervention) vs 19% (Control)
Denneboom, 2007^34^; n=738; 6 months | % of recommendations leading to a medication change:; Case conference group: 29.8% vs 17.2% in written feedback group, P=.02; % of maintained medication change at 6 months: 25.5% vs 14.8%, P=.03
Haag, 2016^46^; n=25; 1 month | No difference between groups in any of multiple measure of PIMs
Hanlon 1996, Schmader 1997^47,92^; n=208; 3, 12 months | MAI scores improved by 24% in the intervention group compared to 6% in the control group (adjusted change score −4.3 compared to −1.1, P=.0006) at 3 months and persisted through 12 months
Köberlein-Neu, 2016^53^; n=142; 15 months | MAI scores were lower (ie, better) in the intervention phase compared to the control phase (mean difference −4.51, 95% CI −6.66 to −2.36, P<.001); mean difference in PIMs: −0.04 (95% CI: −0.09 to 0.01)
Meredith, 2002^67^; n=259; 6–12 weeks | Intervention resulted in a decrease in therapeutic duplications (71% intervention vs 24% control, P=.003) and “more appropriate” cardiovascular medication regimens (55% vs 18% in controls, P=.02); no effect on either psychotropic or NSAID use
Moga, 2017^70^; n=50; 8 weeks | MAI score improved in the intervention compared to control (change score: −3.6 +/− 1.1 for intervention vs 1.0 +/− 0.9 for control, P=.04)
Muth, 2018^71^; n=505; 9 months | Adjusted mean difference between groups at 6 months: MAI score 0.7 (95% CI: −0.2 to 1.6)
Olsson, 2012^73^; n=150; 12 months | Change from baseline in % of patients on PIMs was not significant in any of the 3 groups
Shim, 2018^96^; n=160; 6 months | MAI scores were lower (ie, better) in intervention group compared to control group (median score 8.0 [IQR 9.0] vs 20.0 [IQR 16.0], P<.001)
van der Meer, 2018^105^; n=157; 3 months | Odds of a decrease in Drug Burden Index ≥0.5 in intervention vs control: 1.09 (95% CI: 0.45 to 2.63)

CI=confidence interval; IQR=interquartile range; MAI=Medication Appropriateness Index; NSAID=non-steroidal anti-inflammatory drugs; PIM=Potentially inappropriate medications

We were able to calculate standardized mean differences from 5 trials that reported a measure of PIMs,^14,53,70,71^ as shown in Figure 8.^47,92^ In 2 of the 5 trials the intervention effect, as measured by Cohen’s d,^10^ was less than small,^14,71^ in 1 it was small,^53^ and in 2 it was moderate.^47,70,92^

Figure 8 Standardized Mean Differences in Medication Appropriateness Index (MAI) or Potentially Inappropriate Medications (PIMs) Outcomes^*^ * Definitions of outcomes – CMR Studies

Allard 2001: Mean reduction in the number of PIMs

Hanlon 1996: Mean change in MAI scores

Köberlein-Neu 2016: Mean difference in MAI scores

Moga 2017: Mean change in MAI scores for anticholinergic medication

Muth 2018: Mean change in MAI scores

#### Secondary Outcomes: Acute Care Visits and Costs

Acute Care Visits: Acute care visits were reported in 4 studies with a combined enrollment of 2543.^20,24,25,46,50,62,63^ Three studies (2 medium, 1 low risk of bias) reported no intervention effect. The largest (medium risk of bias) reported a significant difference between groups in mean number of emergency department (ED) visits per patient per 6 months^50,62,63^ as shown in Table 4.

Table 4 Acute Care Visits – CMR Studies

Author; Number enrolled; Length of follow-up | Findings
Boyé, 2017^20^; n=612; 12 months | Number with fall-related ED visits:; Intervention:16 (5%); Control: 21 (8%), P=.22
Campins, 2017, 2019^24,25^; n=503; 12 months | Mean number of ED visits per patient:; Intervention: 0.9 (1.5); Control: 1.1 (1.5), P=.06
Haag, 2016^46^; n=25; 1 month | 1 person in each group with an ED visit
Jodar-Sanchez, 2015^50^; Malet-Larrea 2016, 2017^62,63^ (CONSIGUE); n=1403; 6 months | Mean number of ED visits per patient (decreased in both groups):; Intervention: 0.43 (0.83) baseline, 0.19 (0.51) during study; difference 0.24; Control: 0.55 (1.55) baseline, 0.42 (1.21) during study; difference 0.13

ED=emergency department; SD=standard deviation

Costs: Seven studies, all medium risk of bias, reported a comparison of medication costs between the intervention and control groups^20,24,25,34,50,54,62,63,80,107,110^; in 2 studies this was the only cost data reported.^54,107^ Three studies also reported costs of the intervention (eg, time spent by health care professionals to implement the intervention)^24,25,34,110^ and 2 reported more extensive cost-utility and/or cost-benefit analyses.^20,50,62,63,80^

Medication Costs Only: Neither of these trials reported significant differences between intervention and control groups in average monthly costs of medications per patient.^54,107^

Medication Costs and Intervention Costs: In a study of 1188 patients in 4 general practices in the UK, increased costs were reported for both intervention and control groups, but the net increase per patient per month was significantly smaller in the intervention group (difference between groups −4.72 GBP [95% CI: −7.04 to −2.41], P=.0001).^110^ The Spanish trial of 502 participants found decreased costs in both intervention and control group over 1 year but the decrease was greater in the intervention than the control group (−14.3% vs −7.7%, P=.04). The authors estimated that the intervention resulted in an annual reduction in expenditures of 64 euros per patient.^24,25^ The third study, conducted in the Netherlands with 738 participants followed for 9 months, found no net differences in costs between intervention and control groups.^34^

Cost Utility and Cost-Benefit Analyses: In a cost-utility analysis, the IMPROveFALL trial reported that the intervention did not result in a reduction in total fall-related health care costs.^20,80^ The conSIGUE trial conducted a detailed cost-benefit analysis in which health benefits were estimated by assigning a monetary value to quality-adjusted life years gained. The analysis indicated that the intervention saved 97 euros per patient over 6 months.^50,62,63^

### Educational Interventions (k=10)

#### Summary

Nine of 10 trials of educational interventions directed at providers, patients, or both either did not report or did not have a significant effect on 6 of the primary outcomes: all-cause mortality, falls, MACE, delirium, health-related quality of life/functional status, or adverse drug withdrawal events. One trial reported fewer hospitalizations in the intervention group.

Nine trials reported potentially inappropriate medications (PIMs). Six found that compared to control, the intervention was associated with fewer PIMs at the end of the study. The interventions used in these 6 studies were: a direct-to-consumer patient engagement program with targeted educational material provided directly to patients (k=2 low risk of bias trials); provider education plus feedback (k=2, 1 low, 1 medium risk of bias); and a patient education with a provider education plus feedback intervention (k=2, 1 low, 1 medium risk of bias). The 2 studies testing provider education alone did not report an effect on PIMs.

#### Overview of Studies

We identified 10 trials that evaluated the effect of educational interventions directed at either patients (k=1), providers (k=5), or both (k=4).^21,28,64,77,89,91,95,97,112,115^ The control groups were assigned either usual care (k=8) or a sham intervention (ie, targeting drugs that were not of interest, k=2). Two trials were conducted in the US, 3 in Canada, and 5 in Europe. Demographic characteristics of the enrolled patients are shown in Appendix D, Table 8. We judged the risk of bias to be low in half the trials and medium in the other half (Appendix D, Table 9). Outcomes were reported on a total of 2424 patients in the 7 smaller trials and on 252,684 in the 3 larger trials.

#### Primary Outcomes

The outcomes reported were all-cause mortality, falls, hospitalizations, and quality of life/functional status (Appendix D, Tables 10–12).

All-cause Mortality: Reported in 5 trials, there was no difference in all-cause mortality between the intervention and control groups (Figure 9).

Figure 9 Risk Differences in Mortality – Education Studies

* Intervention arms combined

** Not adjusted for cluster design, estimate of the intracluster correlation coefficient (ICC) not provided by trial

† The post-intervention analysis in the publication reported a non-significant difference 0.1 (−0.1 to 0.6). Clustering was accounted for.

Falls: Only 1 trial reported falls outcomes. This medium risk of bias US trial enrolled 169 people age ≥65 at high risk for hospitalization or functional decline. The intervention was enrollment in a chronic care clinic program. There was no difference between intervention and control group in incidence of falls “over past 12 months”: 35.6% versus 43.5%, P=.35.^28^

Hospitalizations: Four trials reported hospitalizations. A low risk of bias cluster randomized trial conducted at 55 primary care practices in Germany that enrolled 604 people age 65 to 84 with at least 3 chronic conditions reported a reduction in days spent in hospital in the intervention compared to the control group (−3.07, 95% CI: −5.25 to −0.89), despite no change in the trial’s primary outcome, number of medications. The intervention was described as narrative medicine-based and consisted of four 4-hour training sessions for the physicians and three 30-minute physician-patient dialog sessions over the 1-year study.^91^

The other 3 trials found no difference in hospitalizations between intervention and control groups. One was a medium risk of bias cluster randomized trial with 9 months of follow-up that tested a provider education and feedback intervention in 69 clinics in Sweden and enrolled 119,910 people age ≥65. Risk difference between intervention and control for 1 or more hospitalizations was 0.2 (95%CI: −0.8 to 1.2).^95^ The second was a medium risk of bias US CRCT that enrolled 169 people age ≥65 at high risk for hospitalization or functional decline. The intervention was enrollment in a half day multidisciplinary chronic care clinic. At 2 years, 34.3% of control vs 36.5% of intervention enrollees had >1 hospitalization, P=.77.^28^

The third study (D-PRESCRIBE) was a low risk of bias trial focused on sedative-hypnotics, first-generation antihistamines, glyburide, and non-steroidal anti-inflammatory drugs (NSAIDs). Sixty-nine pharmacies (489 patients) were randomized to either usual care or a patient and provider educational intervention. The patients were sent educational brochures describing harms of the targeted medications, alternatives, and, for those on sedative-hypnotics, a visual tapering protocol. Their providers were sent a “pharmaceutical opinion”, which is a legal and reimbursable action in Quebec. The study states: “No adverse effects requiring hospitalization were reported”.^64^

Health-related Quality of Life, Functional Status, and Patient Satisfaction (k=2): 1 study, described above, reported no difference between intervention and control group at 24 months, in SF-36 physical function (mean of 37.5 in both groups); Center for Epidemiologic Studies Depression Scale (CES-D) (mean of 14.8 vs 12.4, P=.11); or patient satisfaction with overall medical care (25.3 % vs 40% rated it excellent, P=.13).^28^ The second study, also described above, reported no difference in health-related quality of life as measured on the EQ-5D between the intervention and control group at 12 months of follow-up: mean score: 0.68 versus 0.70, P=.5.^91^

#### Secondary Outcomes – Medication Changes

Medication Changes (k=10) All 10 trials reported 1 or more medication outcomes (Appendix D, Tables 13 and 14). Three reported on total medications^21,91,95^ and 9 reported on inappropriate medications.^21,28,64,77,89,95,97,112,115^

Reduction in Total Number of Medications (k=3): Only 1 of the 3 studies reported a reduction in total number of medications at follow-up (Table 5).

Table 5 Number of Medications at Follow-up – Education Studies

Author; Number enrolled; Length of follow-up | Intervention | Risk of Bias | Total Number of Medications at Follow up
Bregnhoj, 2009^21^; n=212; 12 months | Provider education or provider education plus feedback vs usual care | Medium | The mean change in total medications in the education plus feedback group vs the other 2 groups combined, was −1.03 (95% CI: −1.7 to −0.3)
Schaefer, 2018^91^; n=604; 12 months | Narrative medicine-based physician-patient dialog sessions | Low | Intervention: 7.3,; Control: 6.8, P=.09
Schmidt-Mende, 2017^95^; n=119,910; 9 months | Provider and nurse education/feedback | Medium | Risk difference: number of subjects on ≥ 10 medications: −0.1 (95% CI: −0.5 to 0.3)

CI=confidence interval

Reduction in Potentially Inappropriate Medications (k=9): As shown in Table 6, 9 trials reported potentially inappropriate medications (PIMs) using the MAI or pre-defined lists. Six trials found a significant reduction in PIMs due to education and provider feedback as measured by varying definitions of PIM reduction.

Table 6 Potentially Inappropriate Medications at Follow-up – Education Studies

Author; Number enrolled; Length of follow-up | Intervention | Risk of Bias | PIMs at Follow-up
Bregnhoj, 2009^21^; n=212; 12 months | Provider education or provider education plus feedback vs usual care | Medium | 5-point reduction (ie, improvement) in MAI in combined intervention group (95% CI: −7.3 to −2.6); no change in other groups
Coleman, 1999,^28^; n=169; 24 months | Patient education in chronic care clinic | Medium | Mean number of high-risk medications at 24 months: Intervention: 1.86, Control: 2.54, P=.17
Jager, 2017^112^; n=273; 9 months | Patient education and provider education/feedback | Low | Risk difference between groups in number of subjects with ≥1 PIM per year: 0.9 (0.4 to 2.0)
Martin, 2018^64^; n=489; 6 months | In-person or mailed brochures on harms of targeted medications and for sedative-hypnotics, a visual tapering protocol; providers received a “pharmaceutical opinion” | Low | Complete cessation of fills for targeted drugs: Intervention: 43%, Control: 12% (risk difference 31%, 95% CI: 23 to 38).
Pimlott,2003^77^; n=374; 6 months | Provider education/feedback focus on benzodiazepines | Medium | Change in number of benzodiazepine prescriptions: Intervention: −0.7%, Control: +1.1%, P=.036
Rognstadt, 2013^89^; n=81,810; 12 months | Provider education and feedback | Low | PIMs per 100 patients decreased by 12% (95% CI: 16.8% to 6.9%), intervention vs control
Schmidt-Mende, 2017^95^; n=119,910; 9 months | Provider and nurse education/feedback | Medium | Risk difference in number on ≥10 medications: −0.1 (95% CI: −0.5 to 0.3)
Simon, 2006^97^; n=50,924; 18 months | Provider education and EHR alerts vs alerts alone | Medium | Decrease of 19.7 medications per 10,000 members (Intervention) vs 13.0 (Control), P=.52
Tannenbaum, 2014^115^; n=303; 6 months | Mailed personalized information to patients on the harms of benzodiazepines and a recommendation for tapering | Low | Benzodiazepine discontinuation: Intervention: 27%, Control: 5% (risk difference 23%, 95% CI: 14% to 32%).

CI=confidence interval; EHR=electronic health record; MAI=Medication Appropriateness Index; PIM=potentially inappropriate medication

#### Secondary Outcomes – Acute Care Visits and Costs

Acute Care Visits: Neither of the 2 studies that reported frequency of acute care encounters found any difference between intervention and control groups.^28,95^

Costs: The only study to report costs found no difference between intervention and control groups in total health care costs per year.^28^

### Computer Decision Support Interventions (K=4)

#### Summary of Findings

None of the 4 trials reported primary outcomes.

Two of the 4 trials reported that the intervention resulted in fewer PIMs. The 2 negative studies may have been underpowered to detect a difference; both had shorter duration of follow-up (13 weeks and 16 weeks) than the positive studies (12 and 13 months).

#### Overview of Studies

We included 4 trials that evaluated the effect of a computer decision support intervention.^37,83,84,100^ Two trials were conducted in the US^37,84^ and 2 in Canada.^83,100^ Sample sizes ranged from 128 to 59,680 patients and study periods ranged from 90 days to 13 months. Demographic characteristics of the enrolled patients are shown in Appendix D, Table 15. All 4 trials were considered medium risk of bias (Appendix D, Table 16). In all 4 trials reduction in potentially inappropriate prescriptions was the only outcome reported (Appendix D, Tables 17 and 18).

#### Primary Outcomes

None reported.

#### Secondary Outcomes – Medication Changes

Two of the 4 trials reported a reduction of PIMs in the intervention compared to the control group.

A Canadian cluster randomized trial tested an EHR-based alert system that notified primary care physicians (n=28) providing office-based care to patients age ≥65 of potentially inappropriate prescriptions. The control group was usual care. At 16 weeks of follow-up, there was no difference in frequency of PIMs between intervention and control groups: 0.1% increase in number of PIMs in both groups.^83^

A trial conducted in the VA Connecticut Health Care system enrolled 156 people age ≥65 taking 7 or more medications. The intervention was an HER-based system called Tool to Reduce Inappropriate Medications (TRIM) that identifies PIMs from standard EHR data and input from a telephonic patient assessment; it then generates a patient-specific feedback report and sends it to the prescribing physician. One control group received the intervention without the patient-specific feedback report and another control group was usual care. The primary outcome of the study was a patient assessment of the quality of both communication and shared decision-making between patient and provider. At 90 days there was no difference between the intervention and control group in the number of prescribed medications (13.3 vs 13.8, P=.65).^37^

A Canadian cluster randomized controlled trial included 107 primary care physicians and 12,560 of their patients age >65 years. The intervention was a computer decision support system which alerted the physician to any of 26 prescribing problems, including drug-drug interactions, drug-age contraindications, drug-disease contraindications, and therapeutic duplications. The control group providers were given the same computer hardware and software as the intervention providers, but the software did not generate alerts. At 13 months of follow-up, the number of new PIMs per 1000 visits was lower in the intervention than the control group (RR 0.82, 95%CI: 0.69 to 0.98).^100^

A US trial included 59,680 members of the Kaiser Permanente health care system age ≥65. The intervention was a triggered alert in the EHR when a patient was prescribed 1 of 11 medications considered potentially inappropriate for older adults. The control group was usual care. At 12 months of follow-up there were fewer newly dispensed prescriptions for the targeted medications in the intervention compared to the control group (1.8% vs 2.2%, P=.002).^84^

### Hybrid/Other Interventions (K=3)

#### Overview of Studies

We included 3 trials in this category because they either included interventions from at least 2 of the 3 other categories or were not otherwise classifiable. In all 3 trials the comparison group was usual care. The trials were conducted in Finland,^57,87^ Ireland,^26,27,41^ and Australia.^78^ A total of 1683 patients were followed for 12 months (Appendix D, Table 19). One trial was considered low risk of bias and 2 were considered medium risk (Appendix D, Table 20).

A low risk of bias cluster RCT (OPTI-SCRIPT) conducted in Ireland enrolled 190 people age ≥ 70 from 21 practices. The intervention combined CMR and a computer-based intervention. It included a 30-minute visit by a pharmacist with the physicians that focused on medication reviews and PIMs; a medication review by each physician with web-based pharmaceutical algorithms that identified PIMs and offered alternatives; and provision of patient information on the relevant PIMs and the alternatives.^26,27,41^

An Australian cluster RCT (medium risk of bias) enrolled 20 general practitioners and 849 patients age ≥65. The intervention included provider education and feedback delivered by a pharmacist at 2 meetings for which physicians were reimbursed; a medication risk assessment completed by patients; and a medication review checklist for at-risk patients for which physicians were compensated after completing 10 reviews. The primary outcome was a composite score reflecting the use of benzodiazepines, NSAIDs, and thiazides.^78^

A population-based medium risk of bias trial in Finland randomized 644 home-dwelling people age ≥75 to either a comprehensive geriatric assessment intervention or control. The geriatric assessment (a clinical examination, lab tests, and medication reviews) was conducted by 2 physicians, 2 nurses, 2 physiotherapists, and a nutritionist.^57,87^

#### Primary Outcomes

Primary outcomes reported were all-cause mortality, falls, and health-related quality of life (Appendix D, Table 21–22).

All-cause Mortality: Reported in 1 trial, there were 2 deaths in both the intervention and control groups at 6 months.^26,27,41^

Falls: The 1 trial that evaluated falls found that at 12 months of follow-up, the intervention group had fewer falls (20% vs 30%, OR 0.61, 95% CI: 0.41 to 0.91); fall-related injuries (10% vs 18%, OR 0.56, 95%CI: 0.32 to 0.96); and falls requiring medical attention (6% vs 13%, OR 0.46, 95% CI: 0.30 to 0.70).^78^

Health-related Quality of Life: The 2 trials that evaluated quality of life found no differences between intervention and control groups.^26,27,41,78^

#### Secondary Outcomes – Medication Changes

All 3 trials reported at least 1 medication outcome, and noted an improvement in medication prescribing, as summarized below (Table 7) (Appendix D, Tables 24 and 25).

Table 7 Medication Change Outcomes – Hybrid/Other Studies

Author; Number enrolled; Length of follow-up | Findings
Clyne, 2015, 2016^26,27^; n=190; 12 months | Intervention group patients were less likely to be taking a PIM than control patients (OR 0.32, 95% CI: 0.15 to 0.70, P=.02)
Lampela, 2010^57^; Rikala 2011^87^; n=644; 12 months | Subjects in the intervention group were more likely to have changes to their medication regimen (84%) than those in the control group (73%) (OR 1.9, 95% CI: 1.3 to 2.8)
Pit, 2007^78^; n=849; 4 months | The intervention group was more likely to have an improved medication use composite score compared to control (OR 1.86, 95% CI: 1.21 to 2.85) (composite score reflected use of benzodiazepines, NSAIDs, and thiazide diuretics)

CI=confidence interval; NSAID=non-steroidal anti-inflammatory drug; OR=odds ratio; PIM=potentially inappropriate medication

### Certainty of Evidence for Key Question 1 – Community or Primary Care Studies

Table 8 summarizes the certainty of evidence for critical outcomes in studies comparing CMR to usual care. We found moderate certainty of evidence that CMR interventions probably result in little to no difference in hospitalizations and low certainty of evidence that CMR interventions may reduce by a small amount or make no difference in all-cause mortality, a slight reduction to no difference in falls, and little to no difference in quality of life measures. Delirium, adverse drug withdrawal events, and major adverse cardiovascular events were not reported in the CMR studies.

For education interventions (Table 9), we found moderate certainty of evidence that the education interventions probably result in little to no difference in all-cause mortality or hospitalizations and low certainty of evidence that education intervention may result in little to no difference in quality of life measures or falls. Delirium, adverse drug withdrawal events, and major adverse cardiovascular events were not reported in the education studies.

We did not assess certainty of evidence for the computer decision support or hybrid interventions due to the small number of studies and heterogeneity of the interventions.

Table 8 Certainty of Evidence for Comprehensive Medication Review Interventions Compared to Usual Care in Elderly Populations

Outcome № of participants (studies) | Relative effect (95% CI) | Anticipated absolute effects (95% CI) | | | Certainty | What happens
Outcome № of participants (studies) | Relative effect (95% CI) | Usual Care | Deprescribing-Medication Review | Difference | Certainty | What happens
All-cause Mortality; follow-up: range 1 to 24 months; № of participants: 4495 (12 trials; 11 RCTs pooled n=3875; 1 CRCT n=620) | RCT; Peto OR 0.79; (0.58 to 1.08) | 4.7% | 3.7%; (2.8 to 5) | RCT; 0.9% fewer; (1.9 fewer to 0.4 more) | ⨁⨁◯◯; LOW^a,b^ | Deprescribing interventions based on Medication Review may reduce by a small amount or make no difference in all-cause mortality.
All-cause Mortality; follow-up: range 1 to 24 months; № of participants: 4495 (12 trials; 11 RCTs pooled n=3875; 1 CRCT n=620) | CRCT *; Peto OR 0.57; (0.27 to 1.23) | 6.8% | 4.8%; (1.9 to 8.2) | RCT; 0.9% fewer; (1.9 fewer to 0.4 more) | ⨁⨁◯◯; LOW^a,b^ | Deprescribing interventions based on Medication Review may reduce by a small amount or make no difference in all-cause mortality.
Hospitalizations ( ≥1 admission); follow-up: range 3 to 24 months; № of participants: 2411 (6 RCTs pooled). | RR 1.07; (0.92 to 1.26) | 19.8% | 21.2%; (19 to 25.9) | 1.4% more; (1.6 fewer to 5.1 more | ⨁⨁⨁◯; MODERATE^a^ | Deprescribing interventions based on Medication Review probably result in little to no difference in hospitalizations.
Quality of Life Measures (QoL) assessed with: EQ-5D, SF-12/36 PCS and MCS; follow-up: range 3 to 12 months; № of participants: 3893 (11 trials) | - | - | - | Most trials reported no differences between groups in QoL measures. | ⨁⨁◯◯; LOW^a,c^ | Deprescribing interventions based on Medication Review may result in little to no difference in quality of life measures.
Falls; follow-up: range 3 to 15 months; № of participants: 1613 (4 trials; 3 RCTs n=993; 1 CRCT n=620) | RCT; NA | Range 11–33% | Range 12–37% | Risk differences (range) 1% to 11% | ⨁⨁◯◯; LOW^a,b^ | Deprescribing interventions based on Medication Review may result in a slight reduction to no difference in falls.
Falls; follow-up: range 3 to 15 months; № of participants: 1613 (4 trials; 3 RCTs n=993; 1 CRCT n=620) | CRCT; OR 0.38; (CI NR) | Ranges over time intervals 10–19% | Ranges over time intervals 9–15% | Risk differences (range) 7% to 1% | ⨁⨁◯◯; LOW^a,b^ | Deprescribing interventions based on Medication Review may result in a slight reduction to no difference in falls.
Delirium - not reported
Adverse Drug Withdrawal Events - not reported
Major Adverse Cardiovascular Events (MACE) - not reported

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect

Moderate certainty: We are moderately confident in the effect estimate: The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different

Low certainty: Our confidence in the effect estimate is limited: The true effect may be substantially different from the estimate of the effect

Very low certainty: We have very little confidence in the effect estimate: The true effect is likely to be substantially different from the estimate of effect

CI: Confidence interval; OR: Odds ratio; RR: Risk ratio

Explanations

a Downgraded for study limitations (medium risk of bias)

b Downgraded for imprecision (wide confidence intervals)

c Although nearly all trials reported no significant difference between groups the estimated standardized mean differences exhibited wide confidence intervals

* Not adjusted for cluster design, estimate of the intracluster correlation coefficient (ICC) not provided by trial

Table 9 Certainty of Evidence for Education Interventions Compared to Usual Care in Elderly Populations

Outcome № of participants (studies) | Relative effect (95% CI) | Absolute effects (95% CI) | | | Certainty | What happens
Outcome № of participants (studies) | Relative effect (95% CI) | Usual Care | Deprescribing-Medication Review | Difference | Certainty | What happens
All-cause Mortality; Follow-up: range 6 to 24 months; № of participants: 121,124 (5 CRCTs) | - | Range 1–16% | Range 0.6–16% | Risk differences (range) −1% to 5% Largest study (n=119,910) reported 0.1%; (95%CI −0.1 to 0.6) | ⨁⨁⨁◯; MODERATE^a^ | Deprescribing interventions based on Education probably result in little to no difference in all-cause mortality.
Hospitalizations (≥1 admission); Follow-up: range 9 months; № of participants: 119,910 (1 CRCT); 1 other trial (n=169) reported >1 hospitalization in frail high-risk participants (NS between group)) | NA | 12.6% | 12.8% | 0.2%; (95%CI −0.8 to 1.2) | ⨁⨁⨁◯; MODERATE^a^ | Deprescribing interventions based on Education probably result in little to no difference in hospitalization.
Quality of Life Measures (QoL) assessed with: EQ-5D; Follow-up: range 15 months; № of participants: 601 (1 CRCT) | - | 0.01 | −0.02 | SMD −0.10; (95% CI −0.26 to 0.06) | ⨁⨁◯◯; LOW^a,b^ | Deprescribing interventions based on Education may result in little to no difference in quality of life measures.
Falls; Follow-up: range 24 months; № of participants: 169 (1 CRCT) | | Ranges over time intervals 36–38% | Ranges over time intervals 44% | Risk differences (range) 6% to 8% | ⨁⨁◯◯; LOW^a,b^ | Deprescribing interventions based on Education may result in little to no difference in falls.
Delirium - not reported
Adverse Drug Withdrawal Events - not reported
Major Adverse Cardiovascular Events (MACE) - not reported

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect

Moderate certainty: We are moderately confident in the effect estimate: The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different

Low certainty: Our confidence in the effect estimate is limited: The true effect may be substantially different from the estimate of the effect

Very low certainty: We have very little confidence in the effect estimate: The true effect is likely to be substantially different from the estimate of effect

CI: Confidence interval; NS: Not significant; OR: Odds ratio; RR: Risk ratio

Explanations

a Downgraded for study limitations (medium risk of bias)

b Downgraded for imprecision

## KQ 1A What are the identified elements/components that contribute the most to the effectiveness of deprescribing interventions?

We did not identify any studies that explicitly addressed this question. However, as described above, it appears that performance feedback to providers improves the effectiveness of educational interventions and that follow-up interventions such as phone calls or clinic visits may improve the effectiveness of comprehensive medication reviews.

## KQ 1B Do the effectiveness, comparative effectiveness, and harms of deprescribing interventions vary by patient population, provider factors, or setting?

The included studies were very similar with respect to patient population (older adults taking multiple medications and living in the community) and setting (primary care clinics). Only 1 study explicitly analyzed the effect of provider factors on intervention effectiveness. This Norwegian study of a provider education and feedback intervention reported that physician factors associated with prescribing improvements included age 57–68 years, advanced training in primary care, and working in solo practices.^89,113^

Eleven studies reported the effect of the intervention on use of psychotropic medications, as shown in Table 10. None of the CMR studies (k=3) or the hybrid/other studies (k=3) found an intervention effect, but 4 of 5 trials of an educational intervention reported a reduction in psychotropic use at follow-up.

Table 10 Deprescribing of Psychotropic Medications

Study; Risk of bias/Number enrolled | Targeted Medications | Results: Intervention vs Control
Comprehensive Medication Review
Weber, 2008^107^; Medium/620 | “psychotropics” | No difference in use at 15 months
Van der Meer, 2018^105^; Medium/157 | “psycholeptics/psychoanaleptics” | No difference in “anticholinergic/sedative load” at 3 months
Meredith, 2002^67^; Low/259 | “psychotropics” | No difference at 6–12 weeks
Education (Provider and Patient Directed)
Martin, 2018^64^; Low/489 | “sedatives/hypnotics” | At 6 months absolute risk difference was 34% (95% CI: 25 to 43%) favoring Intervention
Pimlott, 2003^77^; Medium/374 | Benzodiazepines | % change in mean number of prescriptions at 6 months: Intervention: −0.7%, Control: +1.1%, P=.036.
Rognstad, 2013, 2018^89,113^; Low/81,000 | Tricyclics, Antipsychotics, Benzodiazepines | [underlined: Drug]; Tricyclics:; Antipsychotics:; Benzodiazepines: | [underlined: Unadjusted % change (95% CI)]; −17.1 (−19.3 to −14.9); −24.7 (−27.7 to −21.7); −5.7 (−6.7 to −4.7)
Simon, 2006^97^; Medium/50,924 | Benzodiazepines, Tricyclics | “no apparent effect of the intervention on rates of target medication use”
Tannenbaum, 2014^115^; Low/303 | Benzodiazepines | At 6 months, risk difference 23% (95% CI: 14% to 32%) favoring Intervention
Hybrid/Other
Clyne, 2015, 2016^26,27^; Low/190 | Benzodiazepines | Use at 4–6 months in intervention vs control group: OR: 1.31 (95% CI:0.47 to 3.68)
Lampela, 2010^57^; Rikala, 2011^87^; Medium/644 | “psychotropics” | No difference between groups at 1 year
Pit, 2007^78^; Medium/659 | Benzodiazepines | Use at 1 year in intervention vs control group: OR: 0.65 (95% CI: 0.27 to 1.57)

CI=confidence interval; OR=odds ratio

## Key Question 2 What are the identified facilitators and barriers that impact the implementation of deprescribing interventions within large-scale health systems such as VA?

We identified 9 studies that reported on facilitators and barriers that impact implementation of deprescribing interventions in large-scale health systems (eg, VHA, other integrated care delivery organizations, government health authorities) (Appendix D, Table 27). Of these, 5 studies were from community/primary care settings^125,126,128–130^ including 1 in VA,^129^ 1 from a large integrated health care delivery system in the US,^126^ 1 from primary care practices in Germany affiliated with a large health insurer,^130^ and 2 from regional health authorities in Europe.^125,128^ All of the deprescribing interventions in community/primary care settings focused on CMR. One study targeted non-benzodiazepine sedative-hypnotic medications (Z-drugs)^126^ while the remaining studies focused on medications more broadly.

Three of the 9 identified studies were conducted in nursing homes in either Canada,^124^ Europe,^122,127^ or Australia.^123^ Two of these involved educational interventions^122,124,127^ and 1 involved CMR.^123^ Two were focused on anti-psychotic medications.^122,124,127^

The ninth identified study was conducted in an Emergency Department setting within VA.^131^ The intervention was multicomponent and included geriatric order sets.

Information on barriers and facilitators was collected via interviews, focus groups, or surveys with prescribers and staff members. Two studies also included patients/nursing home residents as respondents.^123,126^ The number of individuals who participated in an interview, focus group, or survey pertaining to barriers/facilitators was fewer than 25 in 7 of the studies. Appendix Table 28 contains information on barriers and facilitators identified in each study.

### Patient Perspective

Two studies reported patient perspectives, a study from the US of a medication review intervention to encourage deprescribing of Z-drugs^126^ and a nursing home study from Australia (Table 11).^123^

Table 11 Patient-Reported Facilitators and Barriers to Implementing a Deprescribing Intervention in Primary Care

Facilitators | Barriers
- Treat patients as individuals; - Providing education about safer alternatives to current medication regimen; - Improve quality of prescribing by addressing costs of medication and difficulties associated with taking medications (eg, size, texture, taste) | - Patients did not identify with patient stories presented in education materials they received; - Deprescribing not emphasized by providers; - Not provided with alternatives to current medication regimen

### Prescriber Perspective

#### Comprehensive Medication Review

Table 12 summarizes findings from 5 studies that assessed prescriber perspectives following implementation of CMR in primary care settings.^125,126,128–130^ The 1 study conducted within VA obtained feedback following a quality improvement initiative in 4 rural outpatient clinics.^129^ Another US-based study focused on inappropriate prescribing of Z-drugs.^126^

Table 12 Prescriber-Reported Facilitators and Barriers to Implementation of Comprehensive Medication Review as a Deprescribing Intervention in Primary Care

Facilitators | Barriers
- Development of work routines for implementing the intervention recommendations; - Collaboration involving all key individuals (including patients and the public); - Better use of skills available within a practice (including optimal use of practice pharmacists); - Shared electronic medical records and prescribing tools; - Shared learning with interprofessional team within a practice; - Education (for prescribers) on geriatric prescribing; - Shared evidence on inappropriate polypharmacy to increase awareness; - Patient materials designed to improve self-management abilities; - Home visits for medication review consultations; - Templates for standardized medication lists; - Financial support to hire clinical pharmacists; - Financial support for research and innovation; - Protected time for polypharmacy medication review consultations; - Individualized feedback forms for prescribers with PIM prescribing information | - Too many checklists and guidelines (feasibility, time, impede individual care for patient, ‘question’ provider competence); - Prescriber lack of knowledge; - Prescriber difficulty attending outside workshops; - Changes in trade names of medications; - Lack of availability of clinical pharmacists; - Lack of team (ie, multiprofessional collaboration); - Skepticism towards physician/pharmacist collaboration; - Prescriber lack of belief in need for medication reviews (ie, prescribe correctly from the start); - Potentially providing too much information to patients on medications and side effects (‘unsettling’ for patients, counter to patient satisfaction goals); - Patients reluctance to give up medications (dependence, long-term users don’t identify with the safety concerns); - Lack of continuity in healthcare; - Lack of institutional support and resources; - Inadequate time for medication review; - Inadequate time to access online resources; - Tools for medication review not integrated into practice software

An Australian study from nursing home settings identified inflexible work practices and legislative requirements, a ‘plethora’ of documentation, lack of standardized procedures, untrained or lack or qualified staff, time pressures, and the complexity of facility resident case mix and available medications as barriers to implementation of an intervention focused on quality use of medicines.^123^ Teamwork, communication and effective information exchange, use of information technology, mutual respect and trust of others, qualified and educated staff, and continuing education were identified as facilitators of implementation.

#### Education

Two nursing home-based studies, both focused on appropriate prescribing of anti-psychotic medications, reported on implementation of education interventions.^122,124,127^ Both studies identified barriers related to time and resources. The study from the United Kingdom cited multiple levels of management contributing to communication problems, unclear expectations, and uncertainty about roles as well as confusion about the organizational aims when the program being implemented conflicts with other organizational elements.^122,127^ The study from Canada similarly identified potential for competing priorities when deprescribing initiatives conflict with established care.^124^ Both studies also noted external pressures in working with residents, families, and prescribers or with the public perception of deprescribing where the focus may be on adverse consequences of deprescribing. The skill of the individuals involved in introducing and implementing the intervention was cited by both studies as a facilitator. Critical skills included credibility (knowledge, understanding of context, confidence), listening, communication (team building, relationships with colleagues), and adaptability. The study from Canada also cited direct involvement of administrators, physicians, pharmacists, and front-line staff with implementation leaders as a facilitator.

#### Computer Decision Support

A VA study of computer decision support in the emergency department identified several barriers to implementation including loss of autonomy (ie, desire to make prescribing decisions based on medical experience) and comfort level with existing order menus and prescribing reminders already posted in the facility.^131^ Those actively using the system (including those who used computerized geriatric order sets at least once as well as those using order sets at least once per shift) reported that time needed to learn the system was a barrier and cited non-intuitive navigation and the need to change prescribing behavior. However, several facilitators were also identified, including potential for improved safety (ie, reducing the risk of adverse events) and efficiency (ie, saving time). Some providers viewed the intervention as a resource for information and as a tool that would be useful for training other providers. Among active users of the system, the location of the geriatric order sets within the emergency department orders, the categorical organization, and the prepopulated fields were facilitating factors.

#### Summary of Findings

Nine studies assessed barriers or facilitators of implementing a deprescribing intervention in a large health care system as part of the implementation process. All reported on provider perspectives; 2 reported patient perspectives. Barriers and facilitators of implementation included patient, provider, and system factors.