# Methods

## Topic Development

The key questions and scope of this review were developed with input from the Operational Partners, Technical Expert Panel, and content experts from out project team.

## Search Strategy

We searched MEDLINE from 1990 to February 2019 using Medical Subject Headings (MeSH) and key words for deprescribing, medication review, medication therapy management, decision support systems, geriatric assessment, electronic health records, medical order systems, polypharmacy, aged population, and Veterans (Appendix A). We searched Embase, the Cumulative Index of Nursing and Allied Health (CINAHL), and the Cochrane Library using search strategies based on the MEDLINE strategy. We did a supplemental search from 1990 to July 2019 of the same databases focused on identifying studies pertaining to barriers and facilitators of implementation using MeSH terms and key words for qualitative research, implementation, barriers, and facilitators (Appendix A).

## Study Selection

Citations were entered into Distiller SR (Evidence Partners). Titles and abstracts were reviewed independently by 2 reviewers with a citation moving to full-text review if either reviewer considered the citation eligible. At full-text review, agreement of 2 reviewers was needed for study inclusion or exclusion. Disputes were resolved by discussion with input from a third reviewer, if needed.

For Key Question 1, we included trials comparing implementation of a deprescribing intervention to usual care or another intervention among individuals age 65 years and older and reporting outcomes of interest. Outcomes included patient-centered outcomes, intermediate process outcomes, and intermediate biomarker outcomes as well as harms, as shown on the analytic framework (Figure 1).

For Key Question 2, we included trials, observational studies, and qualitative research reporting barriers and facilitators associated with implementation of a deprescribing intervention. Most of the included studies interviewed prescribers or intervention staff following implementation of the intervention in a population of individuals age 65 years and older.

Study exclusion criteria were as follows:

- Not a population of interest (eg, children or adults <65 years or mean age <65 years);
- No intervention;
- Not an intervention of interest (eg, intervention to reduce opioid use);
- No concurrent comparator group (Key Question 1 only);
- No outcomes of interest;
- Not a study design of interest:
  ○ KQ1: study design other than randomized controlled trial (RCT), cluster randomized controlled trial (CRCT), or controlled clinical trial (CCT)
  ○ KQ2: study design other than trials, observational studies, or qualitative research
  ○ Narrative reviews, case report/case series, editorials, letters (other than “Research Letters”), theses/dissertations are excluded;
- Full text of article not available in English.

## Data Abstraction

For Key Question 1, we completed full data abstraction from eligible studies conducted in community or primary care settings. From those studies, we abstracted study design and demographic data from eligible studies including study inclusion and exclusion criteria, description of intervention and control arms, and age, gender, race/ethnicity, comorbidity status, physical status, cognitive status, and baseline number of medications. We also abstracted outcomes data for outcomes and harms depicted in Figure 1. Data were abstracted by 1 investigator or research associate and verified by a second. Data abstraction tables were organized by intervention category – comprehensive medication review (CMR), education, computer decision support, or hybrid/other.

For studies conducted in nursing home, hospital, emergency department, or palliative care settings, we abstracted data to prepare an evidence map with key features of the eligible studies. Included data points were country or region where the study was conducted, setting, study design, number enrolled, intervention category, length of follow-up, primary outcome, and outcome categories reported. Information was abstracted by 1 investigator or research associate and verified by a second, Outcomes were grouped as medication change, resource utilization/cost, clinical, or functional status/quality of life/patient satisfaction outcomes. Specific outcomes within each category are presented in Table 1.

For Key Question 2, we abstracted information about the study setting, inclusion criteria for participants, data collection methods, response rates, and participant characteristics. We also abstracted barriers and/or facilitators reported.

Table 1 Outcome Categories for Evidence Map

Medication Changes; Total number of Medications Discontinued; Number of Medications with Dosages Decreased; Number of Medications Added or Substituted; Number of Inappropriate Medications Discontinued; Adherence to Medications; Types of Medications; Medication Burden; Resource Utilization and Costs; Hospitalizations; Acute Care Encounters; Costs; Clinical Outcomes; Falls; Delirium; Major Adverse Cardiovascular Events; Adverse Drug Withdrawal Events; All-cause Mortality; Biomarkers (Glycemic Control; Blood Pressure Control; Cholesterol, Vitamin D, Iron, Thyroid Hormone Levels; Prothrombin Time; Other); Functional Status, Quality of Life, & Patient Satisfaction

## Risk of Bias Assessment

Risk of bias was assessed for community or primary care setting studies included for Key Question 1. Risk of bias of each study was rated by 1 co-investigator or research associate and verified by a second. Overall risk of bias for a study was rated as low, medium, or high after consideration of elements based on the Cochrane risk of bias criteria for randomized trials and cluster randomized trials including sequence generation, allocation concealment, recruitment bias, baseline imbalance, blinded outcome assessment, incomplete cluster data, incomplete outcome data, and selective outcome reporting.^8^

## Data Synthesis

For studies from community or primary care settings (Key Question 1), we pooled results if the studies were deemed low or moderate risk of bias and outcomes measures and study designs were comparable. Data were analyzed in Comprehensive Meta-Analysis version 3 (Biostat). Categorical outcomes data were pooled using the Peto odds ratio (Peto OR) method or risk ratios (RR) with corresponding 95% confidence intervals (CI). Magnitude of statistical heterogeneity was assessed with the I^2^ statistic (I^2^>75% may indicate substantial heterogeneity).^9^ Standardized mean differences (SMDs) between intervention and control groups, with corresponding 95% CIs, were calculated for continuous efficacy outcomes and were interpreted by applying Cohen’s definition of small (0.2), medium (0.5), and large (0.8) effects.^10^ For studies reporting categorical outcomes that were not pooled due to differences in study design and/or definition of the outcome we calculated absolute effects (risk differences) with corresponding 95% CIs for individual trials.

CRCTs were not pooled with RCTs if the adjustment for clustering was not indicated. The unit of randomization for a CRCT is at the cluster level rather than independent individuals and pooling RCTs and CRCTs with inappropriate or unclear adjustment for clustering can lead to misinterpretation of the results.^11^

For intervention studies in settings other than community or primary care and for Key Question 2 findings, results were narratively synthesized.

## Rating the Body of Evidence

For the community- or primary care-based intervention studies, we evaluated overall certainty of evidence for critical outcomes (mortality, hospitalization, quality of life, falls, delirium, adverse drug withdrawal events, and major adverse cardiovascular events) using methods developed by the Grading of Recommendations, Assessment, Development, and Evaluation (GRADE) group.(GRADEpro 2015 accessed at www.gradepro.org).^12,13^ The following domains were used to assess certainty of evidence: 1) risk of bias; 2) consistency; 3) directness; and 4) precision. Certainty of evidence ranges from high (indicating high confidence that the true effect lies close to that of the estimate of the effect) to very low (indicating very little confidence in the effect estimate and that the true effect is likely to be substantially different from the estimate of effect).

## Peer Review

A draft version of this report was reviewed by content experts as well as clinical leadership. Reviewer comments and our responses are presented in Appendix B and the report was modified as needed.