# APPENDIX D Evidence Tables

Appendix D, Table 1 Study Characteristics – Comprehensive Medication Review

Appendix D, Table 2 Risk of Bias – Comprehensive Medication Review Studies

Appendix D, Table 3 Patient-centered Outcomes, Part 1 – Comprehensive Medication Review

Appendix D, Table 4 Patient-centered Outcomes, Part 2 – Comprehensive Medication Review

Appendix D, Table 5 Patient-centered Outcomes, Part 3 – Comprehensive Medication Review

Appendix D, Table 6 Intermediate Process Outcomes, Part 1 – Comprehensive Medication Review

Appendix D, Table 7 Intermediate Process Outcomes, Part 2 – Comprehensive Medication Review

Appendix D, Table 8 Study Characteristics – Education Interventions

Appendix D, Table 9 Risk of Bias – Education Intervention Studies

Appendix D, Table 10 Patient-centered Outcomes, Part 1 – Education Interventions

Appendix D, Table 11 Patient-centered Outcomes, Part 2 – Education Interventions

Appendix D, Table 12 Patient-centered Outcomes, Part 3 – Education Interventions

Appendix D, Table 13 Intermediate Process Outcomes, Part 1 – Education Interventions

Appendix D, Table 14 Intermediate Process Outcomes, Part 2 – Education Interventions

Appendix D, Table 15 Study Characteristics – Computer Decision Support Interventions

Appendix D, Table 16 Risk of Bias – Computer Decision Support Interventions

Appendix D, Table 17 Intermediate Process Outcomes, Part 1 – Computer Decision Support Interventions

Appendix D, Table 18 Intermediate Process Outcomes, Part 2 – Computer Decision Support Interventions

Appendix D, Table 19 Study Characteristics – Hybrid/Other Interventions

Appendix D, Table 20 Risk of Bias – Hybrid/Other Intervention Studies

Appendix D, Table 21 Patient-centered Outcomes, Part 1 – Hybrid/Other Interventions

Appendix D, Table 22 Patient-centered Outcomes, Part 2 – Hybrid/Other Interventions

Appendix D, Table 23 Patient-centered Outcomes, Part 3 – Hybrid/Other Interventions

Appendix D, Table 24 Intermediate Process Outcomes, Part 1 – Hybrid/Other Interventions

Appendix D, Table 25 Intermediate Process Outcomes, Part 2 – Hybrid/Other Interventions

Appendix D, Table 26 Studies Included in Evidence Map

Appendix D, Table 27 Barriers and Facilitators – Study Characteristics

Appendix D, Table 28 Barriers and Facilitators Findings