# APPENDIX C Evidence Map – Nursing Home, Hospital, Emergency Department, and Palliative Care Settings

We identified 48 studies of deprescribing intervention for individuals age 65 and older in emergency department (k=2), hospital (k=21), nursing home (k=24), and palliative care (k=1) settings. Most studies were from Europe (k=29) with 9 from the US (1 in a VA setting), 8 from Australia/New Zealand, 1 from Canada, and 1 from Israel. Overall, sample sizes ranged from 11 to 5,162 with 6 studies enrolling fewer than 100, 25 enrolling between 100 and 500, and 16 enrolling more than 500; 1 study did not report enrollment. Most enrollees were female, and follow-up periods ranged from 0 (a study in an emergency department setting) to 24 months. Study designs included 27 RCTs, 16 cluster RCTs, and 5 CCTs. Of the 48 studies, 45 reported a measure of medication change (medication change was the primary outcome for 36 studies), 27 reported a measure of resource utilization or cost (resource utilization was the primary outcome for 6 studies), 36 reported a clinical outcome (mortality was the primary outcome for 1 study), and 19 reported a measure of functional status, quality of life, or patient satisfaction. Five studies did not specify a primary outcome. Information about each of the studies is provided in Appendix D, Table 26.

Sixty percent of the studies involved CMR (k=29). Ten studies reported on an educational intervention, 3 on a computer decision support intervention, 1 on comprehensive geriatric assessment, and 5 on multicomponent interventions (typically consisting of medication review and provider and/or patient education).

## Key Messages

An evidence map characterizing key study and participant characteristics and reporting outcome of describing interventions identified the following:

- Most studies were conducted in Nursing Home or Hospital settings; little data exist from Emergency Department or Palliative Care settings
- Most studies were conducted in Europe. Only 1 study was conducted in a VA setting.
- Most enrollees were women
- CMR comprised the majority of studied interventions (60%; 29/48 studies)
- Medication change was the primary outcome for the large majority of studies (36/46: 75%) though patient-centered outcomes including mortality, hospitalizations, patient satisfaction, and functional status, as well as costs and resource use, were widely reported.

### Comprehensive Medication Review (CMR)

Appendix C, Table 1 provides an overview of the 29 studies reporting on a CMR intervention. One study was from an emergency department,^22^ 13 from nursing homes,^17,23,31,32,36,38,58,65,69,74,75,82,104,106,111^ 14 from hospitals,^18,33,39,42,45,48,61,68,76,81,93,98,102,108,109^ and 1 from palliative care.^55^

The emergency department study was an RCT from Australia/New Zealand enrolling over 1,000 patients.^22^ The study focused on hospital admissions with a follow-up of 4 months. A medication change outcome was also reported.

The 13 nursing home studies were largely from Australia/New Zealand or Europe and nearly evenly split between RCTs and cluster RCTs. Most enrolled over 100 with fewer than 50% male subjects. More than half had follow-up durations of 6 months or less. Three studies focused on specific medications including psychotropic drugs^74,75,106^ and dopaminergic agents.^104^ Six focused on appropriateness of medications overall^31,32,36,58,69,111^ while 2 addressed the number of medications.^17,82^ The remaining 2 studies focused on reducing costs and resources including staff time.^23,38,65^ Medication change and clinical outcomes were reported in nearly all studies. Fewer reported on resource utilization/cost or functional status, quality of life, or patient satisfaction.

Of the 14 hospital-based studies, 13 were conducted in Europe. The 1 exception was a VA study.^93^ Most studies were RCTS enrolling between 101 and 500 with follow-up durations of 4 months or longer. In several studies, the objective was reducing readmissions^42,45,61,102^ or drug-related problems.^76,93,108,109^ Others focused on reducing the number of medications,^68,81^ particularly inappropriate medications.^18,33,39,48,98^ Nearly all hospital-based studies reported on medication change and clinical outcomes. Fewer reported on resource utilization/costs and functional status, quality of life, or patient satisfaction outcomes were infrequently reported.

The 1 palliative care study was an RCT, conducted in the US, and enrolled 381 patients (55% male).^55^ Follow-up was 12 months. The focus was on discontinuation of statin medications with the primary outcome of mortality within 60 days of enrollment. The study also reported measures of medication change, resource utilization or cost, and functional status, quality of life, or patient satisfaction.

Appendix C, Table 1 Number of Studies Reporting Characteristics of CMR Interventions for Deprescribing in Nursing Home, Hospital, Emergency Department, and Palliative Care Settings (k=29)

Characteristics | Nursing Home; (k=13) | Hospital; (k=14) | Emergency Department; (k=1) | Palliative Care; (k=1)
Country/Region
USA | 2 | 1 (VA-based) | | 1
Canada
Europe | 5 | 13
Australia/New Zealand | 5 | | 1
Other | 1
Study Design
RCT | 6 | 12 | 1 | 1
Cluster RCT | 5
CCT | 2 | 2
Number Enrolled ^a^
≤ 10
11–50 | 2
51–100 | 1 | 2
101–500 | 9^b^ | 11 | | 1
> 500 | | 1 | 1
Percent Male | | | NR
≤ 10 %
11%–30% | 5
31%–50% | 7 | 11
> 50% | 1 | 1^c^ | | 1
Outcomes Reported
Medication Changes | 12 | 13 | 1 | 1
Resource Utilization/Costs | 8 | 9 | 1 | 1
Clinical | 11 | 12 | | 1
Functional Status/Quality of Life/Patient Satisfaction | 7 | 4 | | 1
Follow-up Duration (months)
< 1 | | 2
1–3 | 5 | 2
4–6 | 3 | 4 | 1
> 6 | 5 | 6 | | 1

CCT=controlled clinical trial; CMR=comprehensive medication review; RCT=randomized controlled trial; VA=Department of Veterans Affairs

a Reported sample size indicates number of participants; in CRCTs, effective sample size is less than if single center study

b 1 additional study did not report sample size

c 1 additional studies did not report % male

## Education

We provide an overview of the 10 studies reporting on an educational intervention in Appendix C, Table 2. There were 7 studies in nursing homes^15,29,40,51,52,66,79,94,99^ and 3 in hospital settings.^16,43,103^

The 7 nursing home studies were conducted in the US or Europe and were predominantly cluster RCTs. Although the number enrolled was moderate-to-large, the effective sample size is less due to the cluster design. Most enrolled predominantly women and included follow-up durations of 1 to greater than 6 months. Five studies focused on specific medications including non-steroidal anti-inflammatory drugs^99^ and psychotropic drugs^15,51,52,66,79,94^ while 2 focused more broadly on inappropriate prescribing.^29,40^ All studies reported a measure of medication change with all but 2^66,94^ reporting at least 1 outcome in the other categories of interest.

The 3 hospital-based studies were conducted in Europe or Australia/New Zealand and included 2 cluster RCTs and 1 RCT. One enrolled a small sample size, and in all studies 50% or less of enrollees were male. Follow-up periods were 3 months or less. One of the studies focused on benzodiazepine withdrawal^43^ and another on appropriateness of benzodiazepines.^16^ The third intervention was directed toward reducing adverse drug events.^103^ All studies reported a measure of medication change, 1 reported a measure of functional status, quality of life, or patient satisfaction, and none reported resource utilization, costs, or clinical outcomes.

Appendix C, Table 2 Number of Studies Reporting Characteristics of Education Interventions for Deprescribing in Nursing Home, Hospital, Emergency Department, and Palliative Care Settings (k=10)

Characteristics | Nursing Home; (k=7) | Hospital; (k=3) | Emergency Department; (k=0) | Palliative Care; (k=0)
Country/Region
USA | 3
Canada
Europe | 4 | 2
Australia/New Zealand | | 1
Other
Study Design
RCT | | 1
Cluster RCT | 6 | 2
CCT | 1
Number Enrolled ^a^
≤ 10
11–50 | | 1
51–100
101–500 | 2
>500 | 5 | 2
Percent Male
≤ 10 %
11%–30% | 5
31%–50% | 1^b^ | 2^a^
>50%
Outcomes Reported
Medication Changes | 7 | 3
Resource Utilization/Costs | 4
Clinical | 5
Functional Status/Quality of Life/Patient Satisfaction | 3 | 1
Follow-up Duration (months)
< 1 | | 1
1–3 | 2 | 2
4–6 | 2
>6 | 3

CCT=controlled clinical trial; RCT=randomized controlled trial; VA=Department of Veterans Affairs

a Reported sample size indicates number of participants; in CRCTs, effective sample size is less than if single center study

b 1 additional study did not report % male

## Computer Decision Support

Three RCTs evaluated computer support for deprescribing.^30,35,101^

Two studies were from the US with 1 taking place in an emergency department^101^ and 1 in nursing homes.^35^ The emergency department study included 5,162 patient visits; 35% of the visits were by males. The goal was to examine the effect of decision support on prescribing of potentially inappropriate medications, with the primary outcome being the proportion of emergency department visits by older adults that resulted in at least 1 prescription for an inappropriate medication. No resource utilization, cost, clinical, functional status, quality of life, or patient satisfaction outcomes were reported. Hospital admissions and deaths in the emergency department were excluded.^101^ The nursing home study enrolled 813 patients (29% male). The objective of the study was to determine if implementing a decision support system with specific recommendations for dose and choice of psychotropic drugs would increase prescription of recommended treatment and decrease prescription of non-recommended treatment. The primary outcome was the percentage of psychotropic medication orders that were modified in response to an alert. As in the emergency department study, no resource utilization, cost, clinical, functional status, quality of life, or patient satisfaction outcomes were reported.^35^

The third study was from Canada and was conducted in a hospital setting.^30^ The study enrolled 231 patients with 254 hospitalizations; 40% of the patients were male. The goal of the study was to assess the medication changes implemented for targeted potentially inappropriate medications, with a primary outcome of the number of discontinued drugs or drugs with dosage decreased. Follow-up was 1 month and reported outcomes included medication changes, resource utilization/costs, and clinical outcomes.^30^

## Comprehensive Geriatric Assessment

One RCT from Europe investigated whether medication treatment was more appropriate when hospitalized patients were assigned to a geriatric evaluation and management unit versus general medical wards.^90^ The study enrolled 254 with 35% male. The primary outcome was change in medication regimen from enrollment to hospital discharge. At least 1 clinical outcome was also reported. Length of hospital stay was not reported.

## Multicomponent

Five studies reported on a multicomponent intervention for deprescribing (Appendix C, Table 3).^19,44,49,59,85,86,88^ Three studies were conducted in nursing home settings^44,49,86,88^ and 2 in hospital settings.^19,59,85^

The nursing home studies were cluster RCTs conducted in Australia/New Zealand^88^ or Europe.^44,49,86^ Although the number enrolled was moderate/large, caution in interpretation is needed due to the cluster design. Fewer than one-third of enrollees were male and follow-up periods ranged from 9 to 22 months. One study focused on antipsychotic medications^86^ and 1 on antihypertensive medication.^44,49^ The third study addressed number of prescribed medications with the goal of changing drug use, mortality, and morbidity.^88^ Each of the studies reported on medication change, clinical outcomes, and functional status, quality of life, or patient satisfaction. One study also reported a measure of resource utilization or costs.^88^

Two RCTs, both from Europe, were set in hospitals.^19,59,85^ These studies also enrolled moderate-to-large sample size with approximately 45% male. Both studies had a follow-up duration of 6 months. In both studies, the primary outcome was readmissions or emergency department visits within 6 months of the index hospitalization. Both studies also reported a clinical outcome and 1 study reported a medication change outcome.^19,59^

Appendix C, Table 3 Number of Studies Reporting Characteristics of Multicomponent Interventions for Deprescribing in Nursing Home, Hospital, Emergency Department, and Palliative Care Settings (k=5)

Characteristics | Nursing Home; (k=3) | Hospital; (k=2) | Emergency Department; (k=0) | Palliative Care; (k=0)
Country/Region
USA
Canada
Europe | 2 | 2
Australia/New Zealand | 1
Other
Study Design
RCT | | 2
Cluster RCT | 3
CCT
Number Enrolled ^a^
≤ 10
11–50
51–100
101–500 | 1
>500 | 2 | 2
Percent Male
≤ 10 %
11%–30% | 2^b^
31%–50% | | 2
>50%
Outcomes Reported
Medication Changes | 3 | 1
Resource Utilization/Costs | 1 | 2
Clinical | 3 | 2
Functional Status/Quality of Life/Patient Satisfaction | 3
Follow-up Duration (months)
< 1
1–3
4–6 | | 2
>6 | 3

CCT=controlled clinical trial; RCT=randomized controlled trial; VA=Department of Veterans Affairs

a Reported sample size indicates number of participants; in CRCTs, effective sample size is less than if single center study

b 1 additional study did not report % male