# APPENDIX B Peer Review Comments/Author Responses

Question Text | Comment | Authors’ Responses
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence? | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | Yes - Please see question in the “Additional Suggestions” regarding studies by Amy Linsky et al. on prescriber perceptions. | See response in “Additional Suggestions” section.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | Yes - Polypharmacy and injurious falls in older adults: a nationwide nested case-control study. Morin L, Calderon Larrañaga A, Welmer AK, Rizzuto D, Wastesson JW, Johnell K. Clin Epidemiol. 2019 Jun 24;11:483–493. doi: 10.2147/CLEP.S201614. eCollection 2019. PMID: 3129699931296999 | Thank you for the suggestion. The study by Morin et al. is a nested case-control study and therefore not eligible for inclusion in our review (KQ1).
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | No | Thank you.
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | No | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | This Evidence Synthesis Program is comprehensive and well done. The method of evaluation and analyses used to assess the studies included was well described and excellently conducted. As such, the comments for this review are based on structure versus content, except for a specific question regarding potential studies not included in Key Question 2. All recommended edits follow. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Page 11 Line 43.; The authors should emphasize that the same demographic inclusion criteria were not used for Key Question 2 (i.e. demographics presented in some of the trials are < than mean age of 65 years).; Page 17 Line 43. | We clarified that the demographic inclusion criteria for the population receiving the intervention were the same for both KQs but most information for KQ2 was collected from providers or others involved in implementing the intervention.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Did the authors assess 3 studies by Linsky, Amy et. al. that evaluate prescriber/provider perception in medication discontinuation? Were the studies reviewed and excluded as part of the full text articles identified? If they were not reviewed what was the reason?; Page 23. Line 19 | The studies by Linsky et al. were reviewed and are included in the Discussion section for KQ2. The studies did not focus on a specific deprescribing intervention.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Table 2. The table should be presented in a succinct, descriptive and easy to follow format. Consider breaking findings down into: Intervention, Changes in Medication, Bias. In addition, the studies should be organized into a standard and consistent format either as studies exhibiting a change first vs those without a change, chronological, reverse chronological or alphabetical. The current format of the table takes away from the strength of the information presented.; Page 24. Line 7; Table 3. Similar recommendation to Table 2 however the heading under findings will be for PIM vs Changes in Medications.; Page 76. Appendix C. Table 1. Comprehensive Medication Review | We re-arranged 2 and 3 (and all of the tables in the Results section) by alphabetical order of the study authors.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Table 1. Line 32. Inclusion/Exclusion criteria should have the number of medications separated out on its own line and spaced out from the previous inclusion criteria. This should be done for each study so the reader can easily identify the number of medications. | Thank you for the suggestion. We have the actual number of medications in the Demographics/Characteristics column (note: in final report, Appendix C is now Appendix D)
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Table 1. Line 25. Consider changing demographic title to Demographic/Characteristics.; Page 121. Appendix C. Table 8. Education Interventions | We made the suggested change.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Table 8. Line 32. Same recommendation as in Table 1, CMR.; Recommend placing number of medications on a separate line in the inclusion criteria. | See comment above
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Table 8. Line 26. Consider changing demographic title to Demographic/Characteristics. | This change was made.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | The authors undertook a systematic review of the evidence for interventions focused on deprescribing medications in older adults. Overall this is an excellent effort both in its methods and description. Please see my specific comments below, most of which apply to both the executive summary and full report. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1. Manuscript search and eligibility criteria for KQ2. On page 2 and 11, search and eligibility criteria for both KQ1 and KQ2 are discussed. These questions, the search, and criteria for inclusion are clearly different, but it is unclear from the manuscript, how they are different. For instance, do the exclusion criteria of “no intervention” apply to KQ2 since the KQ2 search criteria used observational studies? These differences should be clarified and include the rationale for in eligibility criteria and the search strategy. | 1. As noted above, we clarified that the demographic inclusion criteria for the population receiving the intervention were the same for both KQs but most information for KQ2 was collected from providers or others involved in implementing the intervention. For KQ2, there had to be a deprescribing intervention (ie, we did not include studies assessing provider attitudes, in general, about deprescribing).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2. It unclear if the 4 categories of intervention (CMR, etc.) were chosen a priori or as a result of the review. The way the report is written leads me to think it was a priori. | 2. Our literature search was broad and not limited to particular intervention types. We organized eligible studies into clinically relevant categories as discussed with our Operational Partners and Technical Expert Panel members.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3. What was the rationale for stratifying the review by in patient vs. outpatient settings. | 3. This was done to manage the scope of the review and to report findings for clinically relevant subpopulations.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4. A large proportion of the papers were excluded in the abstract review phase for both questions. Do the authors have an information on why they were excluded? | 4. We do not track reasons for exclusion at the abstract level.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5. The effect of the intervention on prescribing is listed as a potential mediator of patient-centered outcomes. The effect on this intervening outcome appears to be pretty low (table 2 on page 23). Could this be a primary mediator of the small effect generally seen in patient-centered outcomes? This issue should be identified and discussed in the discussion. | 5. Due to the low number of events and heterogeneity of the studies, there was not enough data to speculate on mediators.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6. Patient perspective on implementation (Page 46). The paragraph at the end of this page is confusing. Perhaps a small table as in the following page would clarify. | 6. Thank you for the suggestion. We replaced the text with a table.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7. Prescriber perspective on interventions (Page 47). Some of the barriers/facilitators listed seem to be intervention specific where as other pertain to a provider’s opinion on the overall concept of deprescribing. Perspectives on both concept seem to be intermingled in this table. Perhaps a separate table, earlier, which lists provider perspectives on the concept of deprescribing irrespective of the intervention used on them. | 7. All of the studies included for KQ2 involved assessment of barriers and facilitators following implementation of a deprescribing intervention. The provider perspectives table represents feedback following implementation of comprehensive medication review. We attempted to clarify this in the text and the table title.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8. Page 6. The authors should clarify what “moderate certainty” means in the executive summary. | 8. We added the definitions regarding certainty to the Executive Summary.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9. Page 7 line 10–14. The first sentence here is very hard to follow. | 9. This sentence was modified.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 10. Page 7 Conclusions. Shouldn’t a main conclusion be the need to increase the evidence (certainty of evidence) on CMR interventions in VA? | 10. We added this point to the Conclusions.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | Additional comments (; Page 4 line 46: Heading “Computer Decision Support” is “computer-based” in line 25; Page 4 line 58: Suggest listing categories at end of bullet to clarify; Page 5 line 20: Key Messages: What was the evidence synthesis for CMR in these settings – it should be listed or reasons why it’s not; Page 5 line 53: Key Messages: “We found few studies” – better to list the number; Page 11 line 47: Still unclear if these exclusion criteria applied to both KQ1 and KQ2? If they did, what was the rationale?; Search and exclusion criteria for KQ2 is confusing. This appears to be a separate search using separate exclusion criteria but how and if it differs from that of KQ1 is still unclear.; Page 46, lines 42–43: Incomplete sentence | Additional comments; Line 46. We made this heading consistent throughout the report.; Line 58. We added the categories.; Line 30. This Key Message refers to the studies included in the Evidence Map. We do not report (or synthesize) findings from those studies.; Line 53. The number of studies has been added.; Line 47. The exclusion criteria were similar for KQ1 and KQ2 and the list of criteria has been modified to show any differences.; Line 42–43. This sentence was modified with the addition of a table summarizing the patient-reported barriers/facilitators.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | This is a very comprehensive and complete systematic review that was conducted in a transparent and rigorous manner. The Summary sections are very helpful. The statements and conclusions were accurately worded, without overstepping the results of the review. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | The only recommendation is to add a couple sentences in the Research Gaps/Future Research section about what sort of trials (e.g., size, duration, etc) would be needed to address the “most glaring gap” of evidence of effectiveness of deprescribing interventions. There have now been several trials of small/moderate size, and the evidence is not strong for intervention effectiveness. Given that the authors are intimately aware of this literature, it would be helpful to readers to know more about their vision for what an ideal trial might look like. | Thank you for the suggestion. The Research Gaps/Future Research section has been revised.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | This report synthesizes the evidence regarding effectiveness of deprescribing in community settings on health and health processes in older adults. Strengths of the report are its clinical question, an a priori analytic framework, its study inclusion criteria (only including prospective controlled trials without high risk of bias), its examination of interventions of different types and potency (medication review, education, and computerized decision support), a good sample size of studies, reasonable homogeneity of aggregated studies, and rigorous analysis and reporting. The following recommendations are suggestions for improvement that would be considered optional:; 1) Consider reporting in each section first the findings related to medication prescribing outcomes (e.g., number of medications, inappropriate medications, etc.) and, following that, reporting patient-centered outcomes (e.g., mortality, falls, hospitalization). This is because a) in many or most studies, the primary outcomes are medication-prescribing outcomes; b) the report’s background and logical framework follows this logic; and c) readers may expect this sequence; i.e., examination of evidence of deprescribing effect on medication use before examining whether deprescribing has an impact on patient health.; Some clarifications and questions:; 2) It would be helpful to know up front when studies are not considered suitable for pooling, and why that is the case;; 3) What is the certainty of evidence for the findings related to medication prescribing outcomes?; 4) A comparison of the demographics (gender, age, ethnicity) in VA vs. non-VA studies may be appropriate to help VA readers understand the similarities and differences - it is mentioned that older non-VA populations are predominantly women but many readers would want to know the actual numbers;; 5) why were the same exclusion criteria used for KQ2 as for KQ1, since it seems that that question would allow studies without comparators, and would not necessarily require outcomes? | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | I was not clear about the start date and completion date for this review (I might have overlooked).; Executive summary and intro were very clear. The charge to ESP was for DePrescribing approaches in the VA settings? There is much reporting on non-VA DePrescribing work…bottomline - not much work is ongoing in the VA with DePrescribing- that message has to be loud and clear. It would be more helpful to review, analyze, report and recommend strategies for CMR - that does not seem to be happening adequately - but is considered helpful as a DePrescribing strategy.; It is startling that no studies addressed the comparative effectiveness of the DePrescribing interventions either with or across categories ) and could be a recommendation for future, and be projected as a gap). Applicability would be insignificant - given there is not much VA related material and most patients are women, and from non VA, outside America.; KQ 1.A : conclusion :: no explicit answers; KQ 1 B. only 1 Norwegian study included providers ( who are the most engaged, who touch the process regularly and almost solely) - this inclusion is critical and is not available.; KQ 2: Again - not much information from within USA. Hard to extrapolate Canadian data to USA VA practice.; Patient perspectives: Very true and are universal and applicable to all. Applicability to the VA from this article/submission is minimal - and potential to invest in such studies within USA, within VA is maximal. Agree with the conclusions. Well captured. | Thank you for your observations.