# APPENDIX A Search Strategies

## Medline Search Strategy (Overall Search)

1. exp “Aged, 80 and over”/ or exp Aged/
2. exp Frail Elderly/ or frail$.ti,ab.
3. (aged or senior$ or elder$ or geriatric$ or veteran$ or dement$ or Alzheimer$ or (“65” adj year$)).ti,ab.
4. exp Veterans/
5. (old$ adj2 (patient$ or person$ or people or adult$ or inpatient$ or outpatient$ or resident$)).ti,ab.
6. exp Homes for the Aged/ or exp Nursing Homes/ or exp Palliative Care/ or exp Hospice Care/ or (“nursing home” or “residential facility” or “retirement village$” or hospice or palliative).ti,ab.
7. exp Drug Utilization/
8. exp Polypharmacy/ or polypharm$.mp.
9. exp Medication Errors/ or exp Inappropriate Prescribing/
10. ((multi-drug$ or multidrug$) adj3 (prescri$ or regimen$ or therap$ or treatment$)).ti,ab.
11. ((excess$ or inappropriate$ or appropriat$ or multi$ or unnecessary) adj3 (drug$ or prescrip$ or prescrib$ or medication$)).mp.
12. ((incorrect or concurrent or concomitant$ or inadvert$ or suboptim$ or sub-optim$) adj3 (drug$ or prescrip$ or prescrib$ or medication$)).mp.
13. ((over adj1 prescri$) or (over-prescri$ or overprescri$)).ti,ab.
14. or/1–5
15. or/6–13
16. 14 and 15
17. exp Deprescriptions/
18. exp Potentially Inappropriate Medication List/
19. (deprescrib$ or de-prescrib$ or deprescipt$ or de-prescript$).ti,ab.
20. (Beer$ adj2 (criter$ or list$)).ti,ab.
21. STOPP.ti,ab.
22. (IPET or “Improving Prescribing”).ti,ab.
23. (ACOVE or “Assessing Care”).ti,ab.
24. (MAI or “Medication Appropriateness”).ti,ab.
25. (“GP-GP” or “good palliative”).ti,ab.
26. (FORTA or “fit for the aged”).ti,ab.
27. PRISCUS.ti,ab.
28. (RASP or “rationali#ation of polypharmacy”).ti,ab.
29. (PIM or “potentially inappropriate medication”).mp.
30. (Garfinkel adj2 (algorithm or method)).ti,ab.
31. (DBI or “drug burden index”).ti,ab.
32. ((improv$ or quality or quantit$) adj3 (drug$ or prescrip$ or prescrib$ or medication$)).mp.
33. Medication therapy management.mp. or exp Medication Therapy Management/
34. exp Medication Reconciliation/ or exp Drug Utilization Review/
35. (“multidisciplinary team” or “case conference” or “patient care team” or care program$).ti,ab.
36. exp “Drug-Related Side Effects and Adverse Reactions”/
37. ((medication$ or drug$) adj2 (review$ or reconciliation)).ti,ab.
38. Decision support systems.mp. or exp Decision Support Systems, Clinical/
39. ((medica$ or clinical or computer$) adj2 decision).ti,ab.
40. exp Geriatric Assessment/
41. exp Electronic Health Records/
42. exp Medication Errors/pc [Prevention & Control]
43. exp Medical Order Entry Systems/
44. (CPOE or (“computeri#ed” adj2 “order entry”)).ti,ab.
45. ((medication or prescri$ or drug) adj2 (manage$ or review$ or reconciliation or error$)).ti,ab.
46. ((Electronic or e-) adj2 (prescri$ or medication$)).ti,ab. or exp Electronic Prescribing/
47. exp Communication/ or exp Inservice Training/ or exp Nursing staff/education
48. or/17–47
49. 16 and 48
50. limit 49 to english language
51. limit 50 to yr=“1990 -Current”
52. randomized controlled trial.pt.
53. controlled clinical trial.pt.
54. exp Randomized Controlled Trial/
55. (random$ adj (enroll$ or assign$ or allocat$)).ti,ab.
56. ((randomi#ed or non-randomi#ed or nonrandom#ed or controlled or placebo or clinical) adj2 trial$).ti,ab.
57. or/52–56
58. 51 and 57

## Medline Search Strategy (Barriers and Facilitators Search)

1. exp “Aged, 80 and over”/ or exp Aged/
2. exp Frail Elderly/ or frail$.ti,ab.
3. (aged or senior$ or elder$ or geriatric$ or veteran$ or dement$ or Alzheimer$ or (“65” adj year$)).ti,ab.
4. exp Veterans/
5. (old$ adj3 (patient$ or person$ or people or adult$ or inpatient$ or outpatient$ or resident$)).ti,ab.
6. exp Homes for the Aged/ or exp Nursing Homes/ or (“nursing home” or “residential facilit$” or “retirement village$” or hospice or palliative).ti,ab.
7. exp Drug Utilization/
8. exp Polypharmacy/ or polypharm$.mp.
9. exp Medication Errors/ or exp Inappropriate Prescribing/
10. ((multi-drug$ or multidrug$) adj3 (prescri$ or regimen$ or therap$ or treatment$)).ti,ab.
11. ((excess$ or inappropriate$ or appropriat$ or multi$ or unnecessary) adj3 (drug$ or prescrip$ or prescrib$ or medication$)).mp.
12. ((incorrect or concurrent or concomitant$ or inadvert$ or suboptim$ or sub-optim$) adj3 (drug$ or prescrip$ or prescrib$ or medication$)).mp.
13. ((over adj1 prescri$) or (over-prescri$ or overprescri$)).ti,ab.
14. or/1–5
15. or/6–13
16. 14 and 15
17. exp Deprescriptions/
18. exp Potentially Inappropriate Medication List/
19. (deprescrib$ or de-prescrib$ or deprescipt$ or de-prescript$).ti,ab.
20. ((improv$ or quality or quantit$ or discontinue$ or withdraw$ or ceas$ or cessation or reduc$ or optim$) adj3 (drug$ or prescrip$ or prescrib$ or medication$ or medicine$ or polypharmacy)).mp.
21. or/17–20
22. exp “Attitude of Health Personnel”/
23. exp Qualitative Research/
24. exp Implementation Science/
25. exp Quality Improvement/
26. exp Interviews as Topic/
27. exp Focus Groups/
28. exp “Surveys and Questionnaires”/
29. (barrier$ or facilitator$ or enabler$ or belief$ or perception$ or attitude$ or perspective$ or preference$ or insight$ or experience$).ti,ab.
30. (interview$ or discussion$ or questionnaire$ or “focus group$” or qualitativ$ or survey$).ti,ab.
31. or/22–30
32. 16 and 21 and 31
33. limit 32 to (address or autobiography or bibliography or biography or case reports or clinical trials, veterinary as topic or comment or congress or consensus development conference or consensus development conference, nih or dataset or dictionary or directory or editorial or “expression of concern” or festschrift or historical article or interactive tutorial or introductory journal article or lecture or legal case or legislation or letter or news or newspaper article or observational study, veterinary or patient education handout or periodical index or personal narrative or portrait or twin study or video-audio media or webcasts)
34. 32 not 33
35. limit 34 to (english language and humans and yr=“1990 -Current”)