# REFERENCES

1 Glisson C. The Role of Organizational Culture and Climate in Innovation and Effectiveness. Hum Serv Organ Manag Leadersh Gov. 2015;39(4):245–250. doi:10.1080/23303131.2015.1087770 27595124
2 Schneider B., Ehrhart MG, W. M. Organizational climate and culture. Annu Rev Psychol. 2013;64(361–388)22856467
3 Büschgens T, Bausch A, Balkin DB. Organizational culture and innovation: A meta-analytic review. Journal of product innovation management. 2013;30(4):763–781.
4 Singer SJ, Falwell A, Gaba DM, . Identifying organizational cultures that promote patient safety. Health Care Manage Rev. Oct–Dec 2009;34(4):300–11. doi:10.1097/HMR.0b013e3181afc10c 19858915
5 Hogan SJ, Coote LV. Organizational culture, innovation, and performance: A test of Schein’s model. Journal of Business Research. 2014;67(8):1609–1621.
6 Greene J, Yuthas K, A. T. Training for innovation: evidence to inform evaluation of the VA Innovators Network. 2017.
7 Mokkink LB, de Vet HCW, Prinsen CAC, . COSMIN Risk of Bias checklist for systematic reviews of Patient-Reported Outcome Measures. Qual Life Res. May 2018;27(5):1171–1179. doi:10.1007/s11136-017-1765-4 29260445
8 Cramm JM, Strating MMH, Bal R, Nieboer AP. A large-scale longitudinal study indicating the importance of perceived effectiveness, organizational and management support for innovative culture. Social science & medicine (1982). 2013;83:119–24. doi:10.1016/j.socscimed.2013.01.017 23415046
9 Berg A, Hallberg IR. Effects of systematic clinical supervision on psychiatric nurses’ sense of coherence, creativity, work-related strain, job satisfaction and view of the effects from clinical supervision: a pre-post test design. Journal of psychiatric and mental health nursing. 1999;6(5):371–81.10827645
10 Bunce D, West MA. Self perceptions and perceptions of group climate as predictors of individual innovation at work. Applied Psychology: An International Review. Jul 1995. 2017-09-25 1995;44(3):199–215. doi:10.1111/j.1464-0597.1995.tb01076.x
11 Jarvis C, Kars S, Sheffield R. Healthy Returns: Leadership Learning and Innovation Climate in the UK Health Sector. Proceedings of the 12th European Conference on Innovation and Entrepreneurship. Acad Conferences Ltd; 2017:330–339. Proceedings of the European Conference on Entrepreneurship and Innovation.
12 Nazir S, Qun W, Hui L, Shafi A. Influence of Social Exchange Relationships on Affective Commitment and Innovative Behavior: Role of Perceived Organizational Support. Article. Sustainability. Dec 2018;10(12)doi:10.3390/su10124418
13 Human performance technology: Concepts, methodologies, tools, and applications. Business Science Reference/IGI Global, Hershey, PA; 2019:1946-Chapter xxxix, 1946 Pages.
14 Gozukara I, Colakoglu N, Simsek OF. Development culture and TQM in Turkish healthcare: importance of employee empowerment and top management leadership. Article. Total Quality Management & Business Excellence. Aug 2019;30(11–12):1302–1318. doi:10.1080/14783363.2017.1366266
15 Apekey TA, McSorley G, Tilling M, Siriwardena AN. Room for improvement? Leadership, innovation culture and uptake of quality improvement methods in general practice. Journal of evaluation in clinical practice. 2011;17(2):311–8. doi:10.1111/j.1365-2753.2010.01447.x 20438607
16 Nowak R. Responding to Key Exogenous Changes: The Joint Effect of Network Heterogeneity and Culture of Innovation. Article. International Journal of Innovation Management. May 2019;23(4)doi:10.1142/S1363919619500300
17 Fincham J. Response rates and responsiveness for surveys, standards, and the Journal. . American journal of pharmaceutical education. 2008;72(2)
18 Weng R-H, Huang C-Y, Chen L-M, Chang L-Y. Exploring the impact of transformational leadership on nurse innovation behaviour: a cross-sectional study. Journal of nursing management. 2015;23(4):427–39. doi:10.1111/jonm.12149 24033847
19 Kim SJ, Park M. Leadership, Knowledge Sharing, and Creativity The Key Factors in Nurses’ Innovative Behaviors. Article. Journal of Nursing Administration. Dec 2015;45(12):615–621. doi:10.1097/NNA.0000000000000274
20 Nieboer AP, Strating MMH. Innovative culture in long-term care settings: the influence of organizational characteristics. Health care management review. 2012;37(2):165–74. doi:10.1097/HMR.0b013e318222416b 21720249
21 Muñoz-van den Eynde A, Cornejo-Cañamares M, Diaz-Garcia I, Muñoz E. Measuring innovation culture: development and validation of a multidimensional questionnaire. Advances in Research. 2015:122–141.
22 Mesfin D, Woldie M, Adamu A, Bekele F. Perceived organizational culture and its relationship with job satisfaction in primary hospitals of Jimma zone and Jimma town administration, correlational study. BMC health services research. 2020;20(1):438. doi:10.1186/s12913-020-05319-x 32429882
23 Acar AZ, Acar P. The effects of organizational culture and innovativeness on business performance in healthcare industry. 8th International Strategic Management Conference. Elsevier Science Bv; 2012:683–692. Procedia Social and Behavioral Sciences.
24 Liebe J-D, Esdar M, Thye J, Hubner U. Antecedents of CIOs’ Innovation Capability in Hospitals: Results of an Empirical Study. Studies in health technology and informatics. 2017;243:142–146.28883188
25 Proudfoot J, Jayasinghe UW, Holton C, . Team climate for innovation: what difference does it make in general practice? International journal for quality in health care : journal of the International Society for Quality in Health Care. 2007;19(3):164–9.
26 Anderson NR, West MA. Measuring climate for work group innovation: development and validation of the team climate inventory. Article. Journal of Organizational Behavior. May 1998;19(3):235–258. doi:10.1002/(SICI)1099-1379(199805)19:3<235::AID-JOB837>3.3.CO;2-3
27 Scott S, Bruce R. Determinants of innovative behavior: A path model of individual innovation in the workplace. . Academy of management journal. 1994;37(3):580–607.
28 Caldwell DF, O’Reilly CA. The determinants of team-based innovation in organizations: The role of social influence. . Small Group Research. 2003;34(4)
29 Phung V-H, Essam N, Asghar Z, Spaight A, Siriwardena AN. Exploration of contextual factors in a successful quality improvement collaborative in English ambulance services: cross-sectional survey. Journal of evaluation in clinical practice. 2016;22(1):77–85. doi:10.1111/jep.12438 26303398
30 Liu F-C, Cheng K-L, Chao M, Tseng H-M. Team innovation climate and knowledge sharing among healthcare managers: mediating effects of altruistic intentions. Chang Gung medical journal. 2012;35(5):408–19.23127346
31 Yan D, Wen F, Li X, Zhang Y. The relationship between psychological capital and innovation behaviour in Chinese nurses. Journal of nursing management. 2020;28(3):471–479. doi:10.1111/jonm.12926 31811781
32 Rashid A, Nawaz S, Zaman U. Examining the effect of inclusive climate on public health official’s creative performance: Mediating role of innovation climate. Article; Early Access. Journal of Public Affairs. 2020;doi:10.1002/pa.2273
33 Dackert I. The impact of team climate for innovation on well-being and stress in elderly care. Journal of nursing management. 2010;18(3):302–10. doi:10.1111/j.1365-2834.2010.01079.x 20546470
34 Roen I, Kirkevold O, Testad I, Selbaek G, Engedal K, Bergh S. Person-centered care in Norwegian nursing homes and its relation to organizational factors and staff characteristics: a cross-sectional survey. International psychogeriatrics. 2018;30(9):1279–1290. doi:10.1017/S1041610217002708 29198221
35 Lansisalmi H, Kivimaki M. Factors associated with innovative climate: What is the role of stress? Article. Stress Medicine. Oct 1999;15(4):203–213. doi:10.1002/(SICI)1099-1700(199910)15:4<203::AID-SMI816>3.0.CO;2-B
36 King EB, De Chermont K, West M, Dawson JF, Hebl MR. How innovation can alleviate negative consequences of demanding work contexts: The influence of climate for innovation on organizational outcomes. Article. Journal of Occupational and Organizational Psychology. Dec 2007;80:631–645. doi:10.1348/096317906X171145
37 Weng RH, Huang CY, Huang JA, Wang MH. The cross-level impact of patient safety climate on nursing innovation: a cross-sectional questionnaire survey. Article. Journal of Clinical Nursing. Aug 2012;21(15–16):2262–2274. doi:10.1111/j.1365-2702.2012.04170.x 22788560
38 Sonmez B, Yildirim A. The mediating role of autonomy in the effect of pro-innovation climate and supervisor supportiveness on innovative behavior of nurses. Article; Proceedings Paper. European Journal of Innovation Management. Jan 2019;22(1):41–58. doi:10.1108/EJIM-05-2018-0088
39 West MA, Wallace M. Innovation in health care teams. European Journal of Social Psychology. 1991;21(4):303–315. doi:10.1002/ejsp.2420210404
40 Isaksen S, Lauer K, Ekvall G. Situational outlook questionnaire: A measure of the climate for creativity and change. . Psychological reports. 1999;85(2):665–74.
41 Quinn RE, Spreitzer GM. The psychometrics of the competing values culture instrument and an analysis of the impact of organizational culture on quality of life. Research in Organizational Change and Development 1991;5:15–42.
42 Wang CL, Ahmed PK. The development and validation of the organisational innovativeness construct using confirmatory factor analysis. . European Journal of Innovation Management. 2004;7(4):303–313.
43 Anderson N WM. The Team Climate Inventory: Development of the TCI and its applications in teambuilding for innovativeness. . European Journal of work and organizational psychology. 1996;5(1)
44 Agency NM. Improvement Leaders’ Guide: Building and Nurturing an Improvement Culture. 2005.
45 Siegel S, Kaemmerer W. Measuring the perceived support for innovation in organizations. . Journal of Applied Psychology 1978;63(5):553.
46 West MA. The social psychology of innovation in groups. 1990;
47 Patterson M. Development and validation of an organizational climate measure. 2004.
48 Siegel SM, Kaemmerer WF. Measuring the perceived support for innovation in organizations. Journal of Applied Psychology. 1978;63(5):553.
49 Agency NM. Improvement Leaders’ Guide: Building and Nurturing an Improvement Culture. 2005.
50 Chan YH, Taylor RR, Markham S. The role of subordinates’ trust in a social exchange-driven psychological empowerment process. Journal of Managerial Issues. 2008;20(4):444–467.
51 Hulscher ME, Schouten LM, Grol RP, Buchan H. Determinants of success of quality improvement collaboratives: what does the literature show? BMJ Qual Saf. Jan 2013;22(1):19–31. doi:10.1136/bmjqs-2011-000651
52 Hallberg IR, Hansson UW, Axelsson K. Satisfaction with nursing care and work during a year of clinical supervision and individualized care. Comparison between two wards for the care of severely demented patients. J Nurs Manag. Nov 1993;1(6):297–307. doi:10.1111/j.1365-2834.1993.tb00231.x 26559037
53 Carnevali D, Patrick M. Nursing Management for the Elderly, 2th edn. . JB Lippincott Company; 1986.
54 Ahmed PK. Culture and climate for innovation. European Journal of Innovation Management. 1998;1(1):30–43.
55 Schein EH. Organizational Culture and Leadership (Vol. 2). John Wiley & Sons.; 2010.
56 Amabile TM, Conti R, Coon H, Lazenby J, M. H. Assessing the work environment for creativity. Academy of management journal. 1996;39(5):1154–84.
57 Brunelle J, Frisk D, Benjamin M, Randall P, Sheikh A. Measuring the Impact Of Innovation Activities in Government. 2019.
58 Ekvall G. Organizational climate for creativity and innovation. . European Journal of Work & Organizational Psychology. 1996;5(1):105.
59 Tseng YF, Lee TZ. Comparing appropriate decision support of human resource practices on organizational performance with DEA/AHP model. . Expert Systems with Applications. 2009;36:6548–6558.
60 Kleysen R, Street C. Toward a multi-dimensional measure of individual innovative behavior. J Intell Cap. 2001;2(3):284–296. .
61 Esdar M, Liebe J, Weiß J, Hübner U. Exploring Innovation Capabilities of Hospital CIOs: An Empirical Assessment. . Stud Health Technol Inform. 2017;235:383–387.28423819
62 O’Reilly CA, Chatman J, Caldwell DF. People and organizational culture: A profile comparison approach to assessing person-organization fit. Acad Manag J. 1991;34:487–516.
63 Kwon J. The influence of innovative organization culture to human resource innovation and organizational commitment. J Bus Res 2011;23(1):153–182.
64 Kim N, Lee J. Empirical study on organizational culture types, CEO leadership styles, and behavioral performance. . Korean J Manage 1997;5(1):193–238.
65 Dallner A, Elo A-L, Gambrele F, . Validation of the General Nordic Questionnaire for Psychological and Social Factors at Work. Nordic Council of Ministers Copenhagen, DK Nord. 2000;
66 Qian Y, Zhang Y-Q, Wu J-M, Wang H-C. Development and psychometric test of Nurse Organizational Innovation Climate Scale. Chinese Journal of Nursing. 2016;51(2):243–247.
67 Phillips W. The Organizational Health Survey. 1988:141±160. The 1988 Annual: Developing Human Resources.
68 Jansen JJP, Van Den Bosch FAJ, Volberda HW. Exploratory innovation, exploitative innovation, and performance: Effects of organizational antecedents and environmental moderators. . Management Science. 2006;52(11):1661–1674.
69 Burningham C, West MA. Individual, climate, and group interaction processes as predictions of work team innovation. . Small Group Research. 1995;26
70 Cameron K, Quinn R. Diagnosing and changing organizational culture: Based on the competing values framework. 2011.