# ACKNOWLEDGMENTS

This topic was developed in response to a nomination by Allison Amrhein, MPH, director of operations for VHA Innovators Network, and Brynn Cole, director of programming for VHA Innovators Network for the purpose of understanding how to create a culture of innovation in healthcare settings. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Allison Amrhein, MPH
  Director of Operations, VHA Innovators Network (iNET)
  Discovery, Education and Affiliate Networks
- Brynn Cole
  Director of Programming, VHA Innovators Network (iNET)

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advises on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Anaïs Tuepker, PhD, MPH
  Qualitative Core Director, Center to Improve Veteran Involvement in Care (CIVIC) – VA Portland Health Care System
  Assistant Professor (Research), Division of General Internal Medicine & Geriatrics – Oregon Health & Science University
- Jacen Greene, MBA
  Assistant Director, Homelessness Research and Action Collaborative – Portland State University
- Sara Singer, PhD, MBA
  Professor of Medicine, School of Medicine, and Professor of Organizational Behavior (by courtesy), Graduate School of Business and Freeman Spogli Institute for International Studies – Stanford University

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.