# CONCLUSIONS

While we were able to identify a moderate amount of literature defining and quantitatively measuring culture of innovation in healthcare settings, this area of research has yet to see rigorous evaluations of intervention work or process of changing culture. Such studies would require multi-site studies with large sample sizes and may build from the early work in this area to focus on interpersonal dynamics, leadership, and/or quality improvement collaboratives.

A culture of innovation in a healthcare organization may have implications for quality of care, population health outcomes, cost of care, and employee satisfaction. An organization exhibiting a culture of innovation may be more likely to have an orientation towards improvement and the ability to continuously adapt to changing environment. More work is needed to understand how to build a culture of innovation in healthcare settings and harness the benefits of culture of innovation as the link between effective organizational practice and high-quality healthcare, thus improving system, clinical, and patient outcomes.