# DISCUSSION

In this systematic review we describe how “culture of innovation” has been defined and measured in studies that have measured or sought to improve or establish a “culture of innovation” in healthcare settings. We identified 4 programs with culture of innovation outcomes.

## SUMMARY OF KEY QUESTIONS

### KQ1 How is culture of innovation defined in literature related to healthcare settings?

When reviewing the included studies, there were several ways that terminology and definition captured the concept of “culture of innovation.” The variations on the terminology and key words used to describe this concept were 1 source of variety. In addition, some studies provided explicit definitions or explanations of culture of innovation; nearly all the publications provided citations related to the concept of culture of innovation. The works of Anderson and West,^26^ Scott and Bruce,^27^ and Caldwell and O’Reilly^28^ appeared numerous times and stood out as noteworthy exceptions in their more consistent use.

While the specific citations may have varied somewhat, nearly all studies related to Anderson and West referred to the “Support for Innovation” domain of the Team Climate Inventory (TCI). The other 3 domains are vision, participation, and task orientation.^26^ Scott and Bruce included 2 dimensions in their definition of “climate for innovation”: resource supply and support for innovation. Caldwell and O’Reilly examined “group variables associated with innovation, particularly norms that develop within a group.”^28^ Four domains emerged from their work: support for creativity and risk taking, teamwork, speed of action, and tolerance of mistakes.

These 3 examples are highly representative of the definitions overall, and there seems to be a loose consensus around the definition for “culture of innovation”. Some common themes extracted from relevant citations include: a shared set of beliefs between people that supported improvement or change, resources to support innovation, and acceptance of change.

### KQ2 What metrics are used to capture culture of innovation in healthcare settings?

Twenty-seven studies measured some version of the construct “culture of innovation” using 26 different instruments. Ten studies administered a single instrument without adaptation, 7 studies modified or truncated an existing instrument, 2 studies developed “homegrown” instruments, and 8 studies incorporated a mix of adapted, homegrown, and/or instrument without modifications. Six instruments were used in more than 1 study to measure “culture of innovation”. TCI and related conceptual work were used in 7 studies, with each study incorporating the 8 items related to “support for innovation” domain within the TCI. Two additional instruments were identified among 3 studies that did not directly measure “culture of innovation”. These studies instead described organizational culture using pre-specified categories. While some instruments were developed in a healthcare setting, others were adapted from other disciplines such as management and economics.

### KQ3 What are key characteristics and outcomes of programs designed to improve or establish a culture of innovation in healthcare settings?

Four studies described programs that reported outcomes using a quantitative measure of culture of innovation. One publication, which described a leadership program in the UK, treated innovation climate as a primary outcome. The other 3 studies included culture of innovation as either a secondary outcome or one of a few various outcomes.

There were similarities between the 4 programs, but no inherent patterns were identified. Three of these studies were larger, including multiple sites, while the fourth study included a smaller sample of nurses from 1 site. Participants in 3 of the studies were frontline healthcare workers, including long-term care providers, nurses, and paramedics. The remaining study included a combination of frontline and senior management. Two programs used QICs with a specific clinical focus: 1 used QI methods to improve acute myocardial infarction and stroke care bundles and the other adapted the Instituted for Health Care Improvement Breakthrough Collaborative method to improve a specific quality topic related to long-term care. Another program incorporated a leadership program aimed at solving a “real world issue” as a group over the course of 8–10 months with a focus on a “relational and experiential approach to learning”. The remaining program was a nurse-led program focused on improving nursing care in a psychiatric ward with a year-long program comprised of group clinical supervision and individual learning about how to plan and document nursing care through nursing diagnosis. While 4 studies with culture of innovation outcomes were identified, their small scale or low response rates and variable details provided about the components of each intervention limited the conclusions to be drawn.

## LIMITATIONS

### Publication Bias

We were not able to test for publication bias and can make no conclusions about its possible existence. However, we supplemented our database search with a Google search to locate possible publications not indexed in traditional databases or published in healthcare journals. The primary challenge for topics without a specific disease or therapy is identifying relevant literature. Because terminology related to culture of innovation is evolving, there are no reliable, standardized terms for systematically searching databases for literature related to this topic, so relevant literature might have been missed. In addition, every healthcare organization has its own culture that is fluid and dynamic, but these changes are not measured/quantified or evaluated, so there are likely real-world examples of successful implementations of innovative culture that are not represented here.

There are several challenges common in literature synthesis studies that also affect this review. The lack of program studies with rigorous study designs limits our ability to draw conclusions about the causal effect of the programs identified on culture of innovation. The low response rates (or no response rate reported) in the majority of studies, especially the program studies identified in KQ3, also introduce uncertainty and potential bias. There is also large variation in the manner in which culture of innovation has been measured. Despite the similarities in how culture of innovation and related constructs were operationalized across studies, there are also vast differences that made interpreting results across studies challenging.

While “culture” and “climate” or “creativity” and “innovation” are often used interchangeably, some researchers have distinguished between these terms in prior literature. Culture is more “observable in the practices and policies of the organization”,^54^ while climate refers to “the behavioral evidence for the culture within an organization”.^55^ Creativity “focuses on the individual thought processes and intellectual activity to general new insights, ideas, or solutions to problems”; innovation extends beyond this notion of creativity by focusing on “the adoption, exploitation and successful implementation of these insights, ideas, or solutions to problems”.^56^ The distinctions between these terms are nuanced but could be important when attempting to identify facilitators and moderators of culture of innovation. Since the goal of this review is to present the breadth of how culture of innovation has been characterized in healthcare settings, our resulting language may lack definitional clarity.

### Applicability of Findings to the VA

None of the identified literature in our searches came from the VA, but there is increasing interest in the concept of culture of innovation and measurement within the VA.^6,^ ^57^ Many healthcare systems are invoking the term “innovation” in programs; however, they vary in their scope, function, and purpose. There are institutions offering competition-type events to encourage advancement of solutions and ideas to improve the quality of healthcare and to build employee capacity through education and training, such as programs at Brigham and Women’s Hospital (Brigham Digital Innovation Hub) and the Henry Ford Innovation Institute. Other institutions, such as Seattle Children Improvement and Innovation (SCII) program or the University of Chicago Center for Healthcare Delivery Science and Innovation, partner with companies to help solve issues facing patients, families, and clinicians with innovative solutions. We were unable to identify evaluations of these programs that described their impact on culture of innovation.

There were only a small number of studies identified within published literature with metrics and interventions. Of those programs that have been published with measurable culture of innovation outcomes,^8,^ ^9,^ ^11,^ ^29^ the studies conducted at United Kingdom’s National Health Service (NHS) would best approximate the VA’s setting, given the scale of the organization and the type of work NHS has been doing. The NHS’ sustained work may be the best place for the VA to gain insight.

## RESEARCH GAPS AND RECOMMENDATIONS FOR FUTURE RESEARCH

This review identified numerous ways “culture of innovation” has been defined and measured in healthcare settings. The various ways researchers have tried to measure the construct could be a signal that “culture of innovation” is a unique construct. Broadening the search strategy would likely reveal the overlap between culture of innovation and other related constructs, such as organizational learning and patient safety culture. More work is needed to refine the definition and critically assess the dimensions and subscales different researchers have attached to this construct.

There is also overlap between research on fostering leadership and research on fostering innovation. One of the included studies from NHS where a leadership training program used innovation climate as an outcome is a strong example of this.^11^ Questions such as whether some concepts of innovation rely more on innovation from “above” by individuals in formal leadership positions, or if there are other concepts/approaches to innovation rely more on distributed leadership/initiative from “below” are interesting for future research.

There is an increasing body of work dedicated to the understanding of how organizational culture affects team composition and function. Our review included studies discussing development culture, which has been shown to promote innovation and continuous adaptation to changing environment.^14^ More work is needed to examine the relationship between healthcare team composition and culture of innovation.

Another area of interest for future research is to examine how teams can improve and sustain innovative culture over time and what impact innovative culture has on system, clinical, and patient outcomes. How to evaluate and assess effectiveness of programs and interventions implemented to improve or cultivate a culture of innovation is also of interest. As discussed, the majority of empirical research conducted in this area employed a cross-sectional study design, giving only a static view of an organization’s culture of innovation at 1 point in time. Since organizational culture is dynamic and constantly evolving, incorporating longitudinal approaches may capture a more complete picture. Moreover, longitudinal study design would allow for examination of causal relationships between culture of innovation and system, clinical, and patient outcomes.