# RESULTS

## LITERATURE FLOW

We identified 480 potentially relevant citations, of which 164 were included at the abstract screening level. From these, a total of 116 abstracts were excluded: study design (n=73), not healthcare (n=39), and not culture of innovation (n=4). This left 48 publications for full-text review, of which 18 were excluded for the following reasons: not healthcare (n=8), study design (n=5), not culture of innovation (n=4), and unavailable (n=1). A full list of excluded studies from the full-text review is included in Appendix G. A total of 30 publications were identified at full-text review as meeting initial inclusion criteria: 4 publications with intervention/program and metric(s), and 26 publications with metric(s) only. See Figure 1 for literature flow. Descriptions of included publications are available in the Evidence Table (Appendix F).

Figure 1 Literature Flow Chart

## DESCRIPTION OF THE EVIDENCE

We identified 30 publications that met the inclusion criteria. None were randomized controlled trials. One meta-analysis was included.^3^ The majority of studies employed the cross-sectional design; 2 studies imposed a pre-post study design^8,^ ^9^ and 2 studies used a repeated measures design.^10,^ ^11^ One of the included studies was a meta-analysis of 43 studies presenting data for 6341 organizations. In terms of analysis approach, 3 studies provided descriptive statistics only, 20 studies presented descriptive statistics and some sort of quantitative analysis (ie, structural equation modeling, hierarchical linear modeling, linear regression, etc). Four studies included programs or interventions about a culture of innovation.^8,^ ^11–13^ See Appendix F Evidence Tables with more detailed descriptions of individual studies.

Figure 2 Studies with Individual Respondent Sample Size Categorized by Response Rate

Included studies originated from 15 different countries: the United Kingdom (n=7), United States (n=3), Taiwan (n=3), Turkey (n=3), China (n=2), Sweden (n=2), the Netherlands (n=2), and 1 study each from Australia, Ethiopia, Finland, Germany, Norway, Pakistan, South Korea, and Spain. Twenty-six studies were multi-site and 4 were single site. Sample size ranged from 22 to 24,205 for individuals, from a range of 11 to 175 teams or groups. Excluding studies with no individual response rates^14–16^ and the meta-analysis,^3^ 7 studies reported response rate of 80% of higher, 7 studies reported response rate of 60–80%, 9 studies reported under 60% response rate, and 3 studies did not report response rate (Figure 2).^17^

## KEY QUESTION 1 HOW IS CULTURE OF INNOVATION DEFINED IN LITERATURE RELATED TO HEALTHCARE SETTINGS?

When reviewing the included studies, there were several ways that terminology and definition captured the concept of “culture of innovation.” The variations on the terminology and key words used to describe this concept were 1 source of variety. In addition, some studies provided explicit definitions or explanations of culture of innovation. Finally, nearly all the publications provided citations related to the concept of culture of innovation. For details on each of the studies and the terms, definitions, and citations they used, please see Appendix D.

Four studies used the term “innovative behavior” as the phrase related to culture of innovation.^12,^ ^16,^ ^18,^ ^19^ The next most common term was “innovative culture”, which was used by 3 studies.^8,^ ^20,^ ^21^ Four terms were used by 2 studies: “the adhocracy culture”,^22,^ ^23^ “innovative organizational culture”,^19,^ ^24^ “culture for innovation”,^15,^ ^16^ and “support for innovation”.^10,^ ^25^ There were 18 additional terms used by the included studies, many of which used variants of the same key words.

Because many terms were variants on the same language, we also looked for patterns in the key words used. Variants of the word “innovation,” which itself had 14 uses, were used 29 times. The word “culture” was used 12 times, whereas “climate” was used 8 times. Words invoking the collective nature of the concept were also common: “organizational” (n=6), “team”/”teams” (n=3), and “workgroup”/”groups” (n=2). The word “behavior” appeared 5 times. Variations on “support” were used by 4 studies. Some additional terms were used only once, or, in the case of “adhocracy”, twice. The word cloud below includes all variants of terms used, with their size proportional to the number of uses (Figure 3).

Figure 3 Words Used in Key “Culture of Innovation” Terms

While publications varied on whether or not they described key domains or explicit definitions related to their “culture of innovation” terms, all the included publications provided relevant citations. The narrative descriptions of the terms, including definitions, domains or other narrative context for the use of the term, are provided in Appendix D. There were 171 unique citation provided among the included studies, with 20 citations cited more than once. While many were used only once and may only apply to specific clinical professions or settings, the works of Anderson and West,^26^ Scott and Bruce,^27^ and Caldwell and O’Reilly^28^ appeared numerous times and stood out as noteworthy exceptions in their more consistent use.

While the specific citations may have varied somewhat, nearly all studies related to Anderson and West referred to the “Support for Innovation” domain of the Team Climate Inventory metric, described in more detail under Key Question 2, below.^26^ The 4 dimensions—support for innovation, vision, task orientation, participation—and their definitions are detailed in Figure 4.

Figure 4 Dimensions of Support for Innovation, Defined by Anderson and West^26^

Scott and Bruce “viewed individual innovative behavior as the outcome of 4 interacting systems—individual, leader, work group, and climate for innovation”.^27^ Adapting the work of Siegel and Kaemmerer, Scott and Bruce included 2 dimensions in their definition of “climate for innovation”: resource supply and support for innovation. The climate for innovation domain is described in more detail under Key Question 2, below.^27^ The 2 dimensions and their definitions are detailed in Figure 5.

Figure 5 Dimensions of Climate for Innovation^27^

Caldwell and O’Reilly examined “group variables associated with innovation, particularly norms that develop within a group.”^28^ They identified social variables related to innovation from case examples which provided “an understanding of the actual experience of teams in organizations and…a broad range of attributes associated with innovation in teams.” Their work is premised on “the assumption that innovation requires both the development of creative responses and the ability to implement them.” Four domains emerged from their investigation – support for creativity and risk taking, teamwork, speed of action, and tolerance of mistakes – and are described in more detail under Key Question 2, below.^28^ The 4 dimensions and their definitions are detailed in Figure 6.

Figure 6 Group Norms Supporting Innovation^28^

These 3 examples are highly representative of the definitions overall, and there seems to be a loose consensus around the definition for “culture of innovation”. Some common themes extracted from relevant citations include: a shared set of beliefs between people that supported improvement or change, resources to support innovation, and acceptance of change.

## KEY QUESTION 2 WHAT METRICS ARE USED TO CAPTURE CULTURE OF INNOVATION IN HEALTHCARE SETTINGS?

Twenty-seven studies reported using 26 different instruments to measure some version of the construct “culture of innovation”. Nineteen studies employed 1 instrument: 10 studies used an instrument without adaptations,^9,^ ^11,^ ^14,^ ^15,^ ^20,^ ^24,^ ^25,^ ^29–31^ 7 studies modified an existing instrument,^8,^ ^26,^ ^32–36^ and 2 studies developed a “homegrown” instrument.^21,^ ^37^ Eight studies used more than 1 instrument: 1 study adapted an existing instrument and added a “homegrown” composite innovation score;^10^2 studies employed 2 complete instruments;^19,^ ^38^3 studies used 2 modified instruments;^12,^ ^16,^ ^23^ 1 study developed 2 “homegrown” instruments;^18^ and 1 study employed an instrument in its entirety and developed 2 “homegrown” innovation scores.^39^ While some were developed in a healthcare setting, others were adapted from other disciplines such as management and economics.^28,^ ^40–42^ Six instruments were employed to measure “culture of innovation” in more than 1 included study.^27,^ ^28,^ ^43–45^ See Appendix E for a crosswalk denoting studies and the instruments they used.

Seven studies^10,^ ^16,^ ^25,^ ^30,^ ^32,^ ^33,^ ^36^ employed Team Climate Inventory (TCI), developed by Anderson & West.^26^ The TCI was based on the 4-factor model of work group innovation developed by West,^46^ which hypothesized that vision, participative safety, task orientation, and support for innovation are predictive of innovativeness. The 38-item self-report questionnaire measured team climate among healthcare management teams and it is intended to provide an aggregate measure of climate of innovation at the group level.

Two of the 7 studies administered the full TCI,^25,^ ^30^ while 4 studies only included 8 items from 1 of TCI’s domains, Support for Innovation.^10,^ ^16,^ ^32,^ ^33^ One study created a 9-item instrument to measure “climate for innovation” by adding an item from Patterson et al^47^ to the 8-item “support for innovation”.^36^

The items in the “Support for Innovation” domain (Figure 7) examined “the extent to which respondents [felt] a climate encouraging innovation, and new and improved way of doing things, exists in their work groups.”^10^ There are 2 subscales in the domain: 4 items from Siegel and Kaemmerer’s climate for innovation measure, “designed to assess organizational level attributes”,^48^ and 4 items developed by Anderson and West to “tap enacted support for innovation, [which] assessed the extent to which time, cooperation, practical support and resources were given by team members to implement new ideas and proposals.”^26^

Figure 7 Support for Innovation Items from the Team Climate Inventory

Scott and Bruce devised the Climate for Innovation Measure to assess “individual differences with respect to the perception of the innovative climate in an organization”.^27^ They developed a 22-item instrument with 2 subscales and surveyed employees of a large non-healthcare industrial facility in the United States. The 2 subscales are: support for innovation (16 items) and resource supply (6 items). The support for innovation domain was adapted from Siegel and Kaemmerer’s 26-item instrument, Climate for Innovation.^45^ Another measure developed within the same study was the Innovative Behavior measure, which was used by 2 included studies^12,^ ^38^ to measure innovative work behavior (IWB). Consisting of 6 items under a single subscale, this measure assessed the tendency of employees to exhibit innovative behavior.^27^

The National Health Service’s culture of innovation instrument,^49^ developed by the NHS Institute for Innovation and Improvement, was used by 2 included studies seeking to measure culture of innovation.^15,^ ^29^ The 7-dimension instrument measured “the degree to which there are resources, support, and rewards for innovation within practices”.^15^ Organization culture for innovation was measured on 7 dimensions: risk, resources, information, targets, tools, reward, and relationships.

Two studies^8,^ ^20^ employed Group Innovation Inventory (GII), a 36-item instrument aimed “to identify the pattern of norms fostering innovation” with 4 domains: creativity and risk taking (9 items), teamwork (7 items), speed of action (4 items), and tolerance of mistakes (5 items).^28^ Caldwell and O’Reilly developed the GII by asking a large sample of non-healthcare senior-level managers from Asia, Europe, Africa, and the United States to identify “norms or expectations that if widely held would facilitate innovation.”^28^ Responses were summarized and formed the basis of the instrument, reflecting “the informal expectations, beliefs, and group processes seen as important for fostering innovation.”^28^

Other studies reported using instruments without adaptations.^9,^ ^11,^ ^14,^ ^19,^ ^20,^ ^24,^ ^31,^ ^38,^ ^39^ Instruments employed include Innovative Work Behavior (Scott & Bruce),^38^ Situational Outlook Questionnaire (SOQ),^11^ Group Innovation Inventory,^20^ Creative Climate Questionnaire (CCQ),^9^ Climate for Innovation (Siegel & Kaemmerer),^39^ instruments to measure individual innovative behaviors (Kleysen & Street) and innovative organization culture,^19^ an instrument to measure innovation capability of Chief Information Officers (Esdar),^24^ an instrument to measure development culture (Tseng & Lee),^14^ and Nurse Organizational Innovation Climate Scale.^31^

Five studies developed “homegrown” instruments: a composite innovation score,^10^ a total innovation score and a role innovation score,^39^ 2 instruments to measure “innovation climate” and “nursing innovation behavior”,^18^ an instrument to measure “nursing innovation”,^37^ and Radiography of Innovation Culture-Multidimensional Questionnaire (RIC-MQ) to measure “innovative culture”.^21^

Several studies employed adapted or truncated versions of existing instruments.^8,^ ^10,^ ^12,^ ^16,^ ^23,^ ^26,^ ^32–36^ The most frequently adapted instrument is the TCI, discussed above.^10,^ ^16,^ ^32,^ ^33,^ ^36^ Some studies adapted items from existing instruments,^10,^ ^12,^ ^23,^ ^35^ while other studies incorporated parts of validated instruments such as Group Innovation Inventory,^8^ Nordic Questionnaire for Psychosocial and Social Factors at Work,^34^ Climate for Innovation developed by Scott & Bruce,^16^ and Climate for Innovation developed by Siegel and Kaemmerer.^26^

Three of the 30 included studies did not directly measure “culture of innovation” but administered instruments to describe organizational culture using pre-specified categories. Two of the studies used the Competing Values Framework (CVF),^3,^ ^50^ while the third study used the Organizational Culture Assessment Instrument (OCAI), which is derived from CVF.^22^ The CVF can be used to explain “the relationships of culture traits with innovation”^3^ and identify implications of each culture type on organizational culture.^22^ The most common organizational culture found for innovative organizations is the adhocracy (creative or development) culture, which emphasizes “an external and a flexibility orientation.”^3^

## KEY QUESTION 3 WHAT ARE KEY CHARACTERISTICS AND OUCOMES OF PROGRAMS DESIGNED TO IMPROVE OR ESTABLISH A CULTURE OF INNOVATION IN HEALTHCARE SETTINGS?

Four studies described programs that reported outcomes using a quantitative measure of culture of innovation.^8,^ ^9,^ ^11,^ ^29^ One publication, which described a leadership program in the UK, treated innovation climate as a primary outcome.^11^ The other 3 studies included culture of innovation as either a secondary outcome or 1 of a few various outcomes. Three of these studies were larger, including multiple sites,^8,^ ^11,^ ^29^ while the final study included a smaller sample of nurses from 1 site.^9^ Participants in 3 of the studies were frontline healthcare workers, including long-term care providers,^8^ nurses,^9^ and paramedics.^29^ The final study included a combination of frontline and senior management.^11^ Each of these studies is described in further detail below.

Our review found multiple related studies from the UK’s National Health System (NHS), including 1 leadership learning program (Figure 8).^11^ The goal of the study was to “explore the role leadership learning can play in supporting a climate for innovation”, which followed 5 cohorts from senior manager and frontline manager training programs. These 2 programs had similar structures, meeting over the course of 8–10 months for module activities, coaching, evaluation activities, and working as a group to solve a real-world issue. Climate for innovation outcome data were collected from 24 of the 148 program participants. The respondents and their teams completed the Situational Outlook Questionnaire (SOQ) before and after completing the program. Additional data were collected from interviews and surveys around the sustainability and influence of the program’s training on dimensions such as conflict and trust and risk-taking. While the response rate (16%) is very low, this study does signal some potential benefits of leadership training in improving dimensions of climate for innovation including challenge/involvement, freedom, trust/openness, idea-time, playfulness/humor, idea-support, debate, and risk-taking.

Figure 8 Leadership Learning Program

Two studies examined quality improvement collaboratives (QIC) (Figure 9).^8,^ ^29^ QICs were created to “improve quality in a specific area of practice, with expert support, involving multi-professional teams from multiple sites working collaboratively and using quality improvement methods.”^51^ The first QIC study included 22,117 paramedics in 12 ambulance services in the UK, and was focused on training participants on quality improvement (QI) methods and applying these methods to improve acute myocardial infarction and stroke care bundles. The clinical outcomes from this QIC were published separately, and the focus of the included study was on culture of innovation, leadership behavior, and uptake of QI methods. The 2,743 paramedics responding to a survey (12% response rate, from 11 of 12 ambulance services) suggest that participation in the QIC may improve uptake of QI methods and leadership behavior. The second QIC, comprised of 12 collaboratives, adapted the Institute for Healthcare Improvement Breakthrough Collaborative method and “focused on improving 1 specific quality topic [related to long-term care] varying from malnutrition to process redesign”.^8^ The analyses compared data collected before and after the collaborative, with 307 of the 1,161 participants included in the analysis (26% response rate). Findings suggest that QIC participation may not improve innovative culture, but other factors like perceived effectiveness of the QIC, organizational support, and management support played an important role in predicting innovative culture.

Figure 9 Quality Improvement Collaboratives

The final study that included a program was a clinical supervision intervention at 1 general psychiatric ward in Sweden, including 22 nurses (Figure 10).^9^ This intervention involved 1 year of systematic group clinical supervision, using Hallberg’s model,^52^ and each participant supervised individually on how to plan and document nursing care through nursing diagnosis.^53^ All 22 nurses completed the Sense of Coherence scale, the Creative Climate Questionnaire (CCQ), the Work-Related Strain Inventory, and the Satisfaction with Nursing Care and Work Questionnaire before and after implementation of the clinical supervision. This small, single site study found increases in some creative and innovative climate dimensions, but their overall findings were mixed.

Figure 10 Clinical Supervision Intervention

There were similarities between the 4 programs, but no inherent patterns were identified. Three of these studies were larger, including multiple sites, while the fourth study included a smaller sample of nurses from 1 site. Participants in 3 of the studies were frontline healthcare workers, including long-term care providers, nurses, and paramedics. The remaining study included a combination of frontline and senior management. Two programs used QICs with a specific clinical focus: 1 used QI methods to improve acute myocardial infarction and stroke care bundles and the other adapted the Instituted for Health Care Improvement Breakthrough Collaborative method to improve a specific quality topic related to long-term care. Another program incorporated a leadership program aimed at solving a “real world issue” as a group over the course of 8–10 months with a focus on a “relational and experiential approach to learning”. The remaining program was a nurse-led program focused on improving nursing care in a psychiatric ward with a year-long program comprised of group clinical supervision and individual learning about how to plan and document nursing care through nursing diagnosis. While 4 studies with culture of innovation outcomes were identified, their small scale or low response rates and variable details provided about the components of each intervention limited the conclusions to be drawn.