# METHODS

## TOPIC DEVELOPMENT

This topic was developed in response to a nomination by Allison Amrhein, MPH, Director of Operations at VHA Innovators Network and Brynn Cole, BA, Director of Programming at VHA Innovators Network. Key questions were then developed with input from the topic nominator, the ESP Coordinating Center, the review team, and the technical expert panel (TEP). The Key Questions were:

KQ1 How is culture of innovation defined in literature related to healthcare settings?
KQ2 What metrics are used to capture culture of innovation in healthcare settings?
KQ3 What are key characteristics and outcomes of programs designed to improve or establish a culture of innovation in healthcare settings?

## SEARCH STRATEGY

We conducted broad searches using terms relating to “culture of innovation” or “culture of creativity”. We searched Web of Science, Ovid Medline, and PsycINFO from inception to 9/18/2020. See Appendix A for complete search strategy.

We also searched the gray literature on 04/03/20, starting with terms like “building a culture of innovation” in a Google search and then also using the Google-generated search terms “7 ways to create a culture of innovation”, “creating an innovation culture McKinsey”, “how to drive innovation culture”, “culture innovation examples”, “how to foster innovation culture”, “organizational culture and innovation”, “culture strategy innovation”, and “how to measure innovation culture.” From these searches, we reviewed the first 50 hits for studies that would meet eligibility criteria.

## STUDY SELECTION

Three team members working independently screened the titles of retrieved citations. For titles deemed relevant by at least 1 person, abstracts were then screened independently in duplicate by 2 team members. All disagreements were reconciled through group discussion. Full-text review was conducted in duplicate by 2 team members, with any disagreements resolved through discussion. Because we were looking for literature that had real-world applications of culture of innovation measurement or intervention, publications were required to (1) use some specified measure or metric for culture of innovation and/or (2) describe an intervention or program to improve or establish a culture of innovation to be included. See Appendix C for screening criteria.

## DATA ABSTRACTION

Data extraction was completed in duplicate. All discrepancies were resolved with full group discussion. We abstracted data on the following: setting, sample size, response rate, country, study design, data analysis approach, culture of innovation metric(s), other metric(s), culture of innovation terms, culture of innovation definitions, and findings from abstract. See Appendix C for data abstraction form.

## QUALITY ASSESSMENT

Typically, quality assessments are used to describe the risk of bias for outcomes from the evaluation of an intervention. As the majority of our studies did not include interventions, this would not help describe the body of literature we identified overall, nor would it help readers interpret key questions 1 or 2. We were not able to identify an existing assessment or determine a set of criteria that would be suitable to assess quality for studies defining culture of innovation or using a metric, as is the focus of these 2 questions. While there are quality assessment criteria for the development of a metric,^7^ which are used for a primary study developing an instrument, not all our included studies described this process, so these criteria would be inappropriate for studies describing fielding of an existing instrument.

We do describe key characteristics of the included studies, most notably including description of the sample size and response rate, which is key information the audience would need to be able to assess credibility of the included studies.

For the subset of intervention studies, we describe the major risks of bias and their considerable impact on the interpretation of the studies narratively.

## DATA SYNTHESIS

Our review is a narrative analysis. We synthesized descriptions of culture of innovation definitions, metrics, and programs from included publications.

## PEER REVIEW

A draft version of the report was reviewed by technical experts and clinical leadership. Reviewer comments and our response are documented in Appendix B.