# INTRODUCTION

Organizational culture plays a critical role in shaping healthcare delivery environments and service quality. Organizational culture may be defined as shared basic assumptions, values, and beliefs that characterize a setting and influence practices, routines, and priorities.^1,^ ^2^ There are multiple facets of organizational culture (eg, safety culture, innovation culture), and scholarship has increasingly acknowledged the value of focusing on specific types.^3,^ ^4^ Cultures that value and support innovation can foster innovative behaviors, which in turn are associated with positive staff and patient outcomes.^1,^ ^5^ One such culture is a culture of innovation.

Prior efforts have sought to synthesize existing models and describe characteristics of organizational culture that supports innovation.^6^ However, additional work focusing on the practical application of these concepts and relationships in real-world settings is needed. For example, more research is needed to identify programs and interventions that foster a culture of innovation, and to determine how culture of innovation can be evaluated and measured.

This report seeks to extend beyond that by examining 3 key questions:

KQ1 How is culture of innovation defined in literature related to healthcare settings?
KQ2 What metrics are used to capture culture of innovation in healthcare settings?
KQ3 What are key characteristics and outcomes of programs designed to improve or establish a culture of innovation in healthcare settings?