# APPENDIX G CITATIONS FOR EXCLUDED PUBLICATIONS

## Not healthcare (n=8)

1 Burch GSJ, Pavelis C, Port RL. Selecting for creativity and innovation: The relationship between the Innovation Potential Indicator and the Team Selection Inventory. International Journal of Selection and Assessment. 2008;16(2):177–181.
2 Fagerlind Stahl A-C, Gustavsson M, Karlsson N, Johansson G, Ekberg K. Lean production tools and decision latitude enable conditions for innovative learning in organizations: a multilevel analysis. Applied ergonomics. 2015;47:285–291.25479999
3 Jaiswal NK, Dhar RL. Transformational leadership, innovation climate, creative self-efficacy and employee creativity: A multilevel study. International Journal of Hospitality Management. 2015;51:30–41.
4 Lee C-S, Chen Y-C, Tsui P-L, Yu T-H. Examining the relations between open innovation climate and job satisfaction with a PLS path model. Quality & Quantity: International Journal of Methodology. 2014;48(3):1705–1722.
5 Liu Y, Wang W, Chen D. Linking Ambidextrous Organizational Culture to Innovative Behavior: A Moderated Mediation Model of Psychological Empowerment and Transformational Leadership. Frontiers in psychology. 2019;10:2192.31681063
6 Maher L, Plsek P, Bevan H. Creating the culture for innovation: a practical guide for leaders. NHS Institute for Innovation and Improvement; 2009.
7 Sanz-Valle R, Naranjo-Valencia JC, Jimenez-Jimenez D, Perez-Caballero L. Linking organizational learning with technical innovation and organizational culture. Journal of Knowledge Management. 2011;15(6):997–1015.
8 Wang P, Rode JC, Shi K, Luo Z, Chen W. A workgroup climate perspective on the relationships among transformational leadership, workgroup diversity, and employee creativity. Group & Organization Management. 2013;38(3):334–360.

## Qualitative description/Commentary (n=5)

1 Black H, Fitzgerald A. Organisational Climate for Change And Innovativeness: A Social Capital Perspective. Asia Pacific Journal of Health Management. 2018;13(1).
2 Everett LQ, Sitterding MC. Building a culture of innovation by maximizing the role of the RN. Nursing administration quarterly. 2013;37(3):194–202.23744465
3 Garney WR, Wilson K, Nelon JL, . Understanding innovation in health program planning and development. Evaluation and program planning. 2019;73:226–231.30739018
4 Hagle M, Dwyer D, Gettrust L, Lusk D, Peterson K, Tennies S. Development and Implementation of a Model for Research, Evidence-Based Practice, Quality Improvement, and Innovation. Journal of nursing care quality. 2020;35(2):102–107.31290777
5 West MA, Anderson N. Innovation, Cultural-Values, and the Management of Change in British Hospitals. Work and Stress. 1992;6(3):293–310.

## Not culture of innovation (n=4)

1 Bonacci I, Cicellin M, Tamburis O, Galdiero C. "Smart" healthcare organizations. An analysis of the organizational climate in a Hospital Paediatrics ward. Ifkad 2013: 8th International Forum on Knowledge Asset Dynamics: Smart Growth: Organizations, Cities and Communities. Matera: Ikam-Inst Knowledge Asset Management; 2013:1040–1056.
2 Hermer L, Cornelison L, Kaup ML, Poey JL, Stone R, Doll G. The Kansas PEAK 2.0 Program Facilitates the Diffusion of Culture-Change Innovation to Unlikely Adopters. The Gerontologist. 2018;58(3):530–539.28204476
3 Luz S, Shadmi E, Admi H, Peterfreund I, Drach-Zahavy A. Characteristics and behaviours of formal versus informal nurse champions and their relationship to innovation success. Journal of Advanced Nursing. 2019;75(1):85–95.30168170
4 Marques CS, Valente S, Lages M. The influence of personal and organisational factors on entrepreneurship intention: An application in the health care sector. Journal of nursing management. 2018;26(6):696–706.29504177

## Unavailable (n=1)

1 Carlucci D, Mura M, Schiuma G. Fostering Employees’ Innovative Work Behaviour in Healthcare Organisations. International Journal of Innovation Management. 2020;24(2).