# APPENDIX F EVIDENCE TABLES

## STUDIES WITH PROGRAM/INTERVENTION (N=4)

### Studies which measured Culture of Innovation using an instrument without adaptation (n=3)

### Studies which measured Culture of Innovation using an instrument with adaptation (n=1)

## STUDIES WITHOUT PROGRAM/INTERVENTION (N=26)

### Studies which measured Culture of Innovation using a single instrument without adaptation (n=7)

### Studies which measured Culture of Innovation using a single adapted/modified/truncated instrument (n=6)

### Studies which measured Culture of Innovation using more than 1 instrument (n=8)

### Studies which measured Culture of Innovation with “homegrown” instrument (n=2)

### Studies which measured Organizational Culture (n=3)