# APPENDIX E STUDY & METRIC(S) CROSSWALK

## Instruments used in multiple studies (n=7)

- measured culture of innovation (n=6); described organization culture using pre-specified categories (n=1)

Instrument | Study | | | | | | | | | | | | | | | | | Total
| Liu 2012^30^ | Proudfoot 2007^25^ | Sommez 2019^38^ | West 1991^39^ | Phung 2016^29^^ | Apekey 2011^15^ | Nieboer 2012^20^ | Cramm 2013^8^^ | Dackert 2010^33^ | Rashid 2020^32^ | Nowak 2019^16^ | Anderson 1998^26^ | Bunce 1995^10^ | Nazir 2018^12^ | King 2007^36^ | Chan 2008^50^+ | Buschgen 2013^3^+
Team Climate Inventory ^43^ | X | X | | | | | | | A | A | A | | A | | A | | | 7
Climate for Innovation (Scott & Bruce) ^27^ | | | X | | | | | | | | A | | | | | | | 2
Climate for Innovation (Siegel & Kaemmerer) ^45^ | | | | X | | | | | | | | A | | | | | | 2
Culture of Innovation ^44^ | | | | | X | X | | | | | | | | | | | | 2
Group Innovation Inventory ^28^ | | | | | | | X | A | | | | | | | | | | 2
Innovative Work Behavior ^27^ | | | X | | | | | | | | | | | A | | | | 2
Competing Values Model of Organizational Culture ^41^ | | | | | | | | | | | | | | | | O | O | 2

^=study with program/intervention; +=study with organizational culture metric; X=instrument without adaptation; A=adapted/modified/truncated instrument; H=homegrown instrument; O=organizational culture metric

## Instruments used in a single study (n=21)

- measured culture of innovation (n=20); described organization culture using pre-specified categories (n=1)

Instrument | Study
| Berg 1999^9^^ | Gozukara 2019^14^ | Kim 2015^19^ | Liebe 2017^24^ | Nazir 2018^12^ | Roen 2018^34^ | Yan 2020^31^ | Lansisalmi 1999^35^ | Acar 2012^23^ | Bunce 1995^10^ | Jarvis 2017^11^^ | Weng 2015^18^ | Weng 2012^37^ | Munoz-van den Evnde 2015^21^ | West 1991^39^ | Mesfin 2020^22^+
Creative Climate Questionnaire ^58^ | X
Development Culture instrument ^59^ | | X
Individual Innovative Behaviors ^60^ | | | X
Innovation Capability of CIOs ^61^ | | | | X
Innovative Organizational Culture ^62^ | | | | | A
Innovative Organizational Culture^63,^ ^64^ | | | X
Nordic Questionnaire for Psychosocial & Social Factors at Work ^65^ | | | | | | A
Nurse Organizational Innovation Climate Scale ^66^ | | | | | | | X
Organizational Health Survey ^67^ | | | | | | | | A
“Organizational Innovation” (Wang & Ahmed) ^42^ | | | | | | | | | A
“Organizational Innovation” (Janssen) ^68^ | | | | | | | | | A
Propensity to Innovate ^69^ | | | | | | | | | | A
Situational Outlook Questionnaire (SOQ) ^40^ | | | | | | | | | | | X
Composite Innovation Score ^10^ | | | | | | | | | | H
“Innovation Climate” ^18^ | | | | | | | | | | | | H
“Nurse Innovation Behavior” ^18^ | | | | | | | | | | | | H
“Nursing innovation” ^37^ | | | | | | | | | | | | | H
Radiography of Innovation Culture-Multidimensional Questionnaire (RIC-MQ) ^21^ | | | | | | | | | | | | | | H
Role Innovation Score ^39^ | | | | | | | | | | | | | | | H
Total Innovation Score ^39^ | | | | | | | | | | | | | | | H
Organizational Culture Assessment instrument (OCAI) ^70^ | | | | | | | | | | | | | | | | O

^=study with program/intervention; +=study with organizational culture metric; X=instrument without adaptation; A=adapted/modified/truncated instrument; H=homegrown instrument; O=organizational culture metric