# APPENDIX D DEFINITIONS TABLE

Author, year | In-text Definition | Citation
Nowak 2019^16^ | …culture of innovation that is defined in this paper as a culture that mandates employee engagement and support for the process of organisational change (eg, Anderson and West, 1998; Scott and Bruce, 1994).; Prior literature has also investigated the role of organisational culture within context of the process of internal change, proposing that a firm’s cultural norms may dictate employee engagement in innovative behaviours by creating a strong expectation that employees must engage in such behaviours as information sharing, feedback providing, collaborative-problem solving, and generating and supporting new process improvement ideas (eg, Zahra et al., 2004; West and Anderson, 1996; Scott and Bruce, 1994). According to West and Anderson (1996), this culture generates “the expectation, approval, and practical support of attempts to introduce new and improved ways of doing things in the work environment” (West and Anderson, 1996, p. 686). | Anderson, NR and MA West (1998). Measuring climate for work group innovation: development and validation of the team climate inventory. Journal of Organizational Behavior: The International Journal of Industrial, Occupational and Organizational Psychology and Behavior, 19(3), 235–258.; Scott, SG and RA Bruce (1994). Determinants of innovative behavior: A path model of individual innovation in the workplace. Academy of Management Journal, 37(3), 580–607.; West MA and NR Anderson (1996). Innovation in top management teams. Journal of Applied Psychology, 81(6), 680.; Zahra SA, JC Hayton and C Salvato (2004). Entrepreneurship in family vs. non-family firms: A resource-based analysis of the effect of organizational culture. Entrepreneurship Theory & Practice,28(4),363–381.
Phung 2016^29^ | Box 3 [Seven dimensions measuring organizational culture of innovation]: Risk taking; Resources for innovation; Widely shared knowledge; Specific targets; Tools and techniques; Reward systems; Rapidly formed relationships | 25. Great Britain.NHS Modernisation Agency (2005) Improvement Leaders’ Guide: Building and Nurturing an Improvement Culture. London: Department of Health.
Apekey 2011^15^ | For improvement to occur, organizations require effective leadership, a culture supporting innovation, the assimilation of technical skills and structures for coordinating and monitoring change [7]. Culture is a ‘shared set of (implicit and explicit) values, ideas, concepts, and rules of behaviour that allow a social group tofunction and perpetuate itself.’ [8] Cultural resistance is thought to arise from a lack of vision, poor organization, teamwork or attitudes and deficient learning [9]. The culture for improvement within practices was evaluated using an instrument designed by the NHS Institute for Innovation and Improvement [22] where respondents rated their organization’s current culture for innovation using 7 dimensions on a ‘Spider Diagram’ (Fig. 1), an instrument measuring the degree to which there were resources, support and rewards for innovation within practices (Box 1[Dimensions of organizational culture for innovation]): Risk; Resources; Information; Targets; Tools; Reward; Relationships | 7. Huntington J., Gillam S. & Rosen R. (2000) Clinical governance in primary care: organisational development for clinical governance. BMJ, 321, 679–682.10987774; 8. Hudelson, P. M. (2004) Culture and quality: an anthropological perspective. International Journal for Quality in Health Care, 16, 345–346.15375093; 9. Stevenson K. & Baker R. (2009) Investigating organisational culture in primary care. Quality in Primary Care, 13, 191–200.; 22. Great Britain. NHS Modernisation Agency (2005) Improvement Leaders’ Guide: Building and Nurturing an Improvement Culture. London: Department of Health.
Liebe 2017^24^ | Chief information officers (CIOs) stand at the heart of corresponding management activities [4]. Their perceived ability to initialise, implement and institutionalise new and suitable HIT solutions can be defined as innovation capability [5], a construct composed of latent personal and organizational characteristics. These are in detail: an innovative organisational culture and the CIOs’ intrapreneurial personality and openness towards users [6]. Innovative organizational culture describes a working environment that nurtures unorthodox thinking, which is based on shared values, basic underlying assumptions and observable artifacts [7,8]…With regard to HIT, innovative organisational culture can be characterised by shared visions about the future role of HIT, by a supportive hospital board (HB) and by a certain degree of flexibility in organisational structures, processes and work routines [3,6]. | [3] Cresswell K, Sheikh A. Organizational issues in the implementation and adoption of health information technology innovations: an interpretative review. Int journal of medical informatics 2013; 82:e73–e86.; [4] Haux R, Winter A, Ammenwerth E, Brigl B. How to Strategically Manage Hospital Information Systems. In: Strategic Information Management in Hospitals. Springer; 2004. pp. 177–220.; [5] Avgar AC, Litwin AS, Pronovost PJ. Drivers and barriers in health IT adoption: a proposed framework. Applied clinical informatics 2012; 3:488–500.23646093; [6] Esdar M, Liebe JD, Weiß JP, Hübner U. Exploring Innovation Capabilities of Hospital CIOs: An Empirical Assessment. Stud Hlth Technol Inform. 2017;235:383–387.; [7] Schein E, H. Organizational culture. American Psychologist 1990; 45:109–119.; [8] Khazanchi S, Lewis MW, Boyer KK. Innovation-supportive culture: The impact of organizational values on process innovation. Journal of Operations Management 2007; 25:871–884.
Buschgen 2013^3^ | Those make up a range from broad variables such as innovation culture (eg, Chandler, Keller, and Lyon, 2000; Gumusluoglu, and Ilsev, 2009) or supportive culture (eg, Abbey and Dickson, 1983; Berson, Oreg, and Dvir, 2008; Wei and Morgan, 2004) to very specific cultural variables like tolerance for failure (Danneels, 2008) or participative decision-making (Hurley and Hult, 1998). | Chandler, G. N., C. Keller, and D. W. Lyon. 2000. Unraveling the determinants and consequences of an innovation-supportive organizational culture. Entrepreneurship Theory and Practice(Fall): 59–76.; Gumusluoglu L., and A. Ilsev. 2009. Transformational leadership and organizational innovation: The roles of internal and external support for innovation. Journal of Product Innovation Management 26: 264–77.; Abbey A., and J. W. Dickson. 1983. R&D work climate and innovation in semiconductors. Academy of Management Journal 26 (2): 362–68.; Berson Y., S. Oreg, and T. Dvir. 2008. CEO values, organizational culture and firm outcomes. Journal of Organizational Behavior 29: 615–33.; Wei Y., and N. A. Morgan. 2004. Supportiveness of organizational climate, market orientation, and new product performance in Chinese firms. Journal of Product Innovation Management 21: 375–88.; Danneels E. 2008. Organizational antecedents of second-order competences. Strategic Management Journal. 29: 519–43.a; Hurley, R. F., and G. T. M. Hult. 1998. Innovation, market orientation, and organizational learning: An integration and empirical examination. Journal of Marketing.62:42–54.
Cramm 2013^8^ | Innovative cultures reportedly enhance the creation and implementation of new ideas and working methods in organizations (Caldwell & O’Reilly, 2003). Innovative cultures reflect attitudes and behaviors of teams as well as the organization and are known to provide a link between effective organizational practice and high-quality healthcare (Mickan & Rodger, 2000; St. John Burch & Anderson, 2003). | Caldwell, D. F., & O’Reilly, C. A. (2003). The determinants of team-based innovation in organisations. The role of social influence. Small Group Research, 34, 497e517.; Mickan S., & Rodger S. (2000). Characteristics of effective teams: a literature review. Australian Health Review, 23, 201e208 11186055; St. John Burch, G., & Anderson N. (2003). What does it take to be a good team player? Assessing team climate preference can help. Select Development Review,19,15–19.
Muñoz-van den Eynde 2015^21^ | the STI Outlook 2012 [3] pointed out that it is increasingly recognized that innovation is influenced by certain social and cultural values, norms, attitudes and behaviors which may be described as innovation culture. In this paper we focus on 3 issues directly related to measuring innovation culture. First, the lack of validated measurement scales of innovation culture [2], necessary to enhance the understanding of innovation culture. Second, the difficulty in identifying the factors determining the tendency and ability of organizations to produce innovations [4], key for diagnostic purposes. Third, the excessive focus on organizations, neglecting the relevance of social factors and individuals. Innovation and culture are social constructs [6]. To say that something is socially constructed is to emphasize its dependence on society.; The social context tends to be ignored when measuring innovation culture. Addressing this issue, it seems appropriate to talk about the social appropriation of innovation, a term from Science, Technology and Society (STS) studies. If this approach is to be accepted, it is necessary to include not only cognitive and economic elements in the concept of innovation, but also social, organizational and cultural aspects. Ultimately, all innovations generate changes due to their adoption or rejection by society [10].; We consider it fundamental to know workers’ perceptions about the influence of this dimension on their ability to do their job. An organization’s innovative capability depends, at least partly, on the innovative traits of its employees [2,11]. Thus, individual differences have to be taken into consideration [16–18]. Another relevant and neglected factor is trust. Trust may be broken down into 2 dimensions: trust among employees, and trust between personnel and leaders [19]. Therefore, it is also important to know which traits in workmates and leaders are valued by employees. | 2. Dobni CB. Measuring innovation culture in organizations. The development of a generalized innovation culture construct using exploratory factor analysis. Eur. J. Innov. Manag. 2008;11(4):539–59.; 3. Organisation for Economic Co-operation and Development. OECD Science, Technology and Industry Outlook 2012. Paris: OECD; 2012.; 4. Wang CL, Ahmed PK. The development and validation of the organizational innovativeness construct using confirmatory factor analysis. Eur. J. Innov. Manag. 2004;7(4):303:13.; 6. Cornejo M, Muñoz E. Percepción de la innovación: cultura de la innovación y capacidad innovadora. In: Pérez Sedeño E., Cimoli M, coordinators. Innovación y Conocimiento. Pensamiento Iberoamericano. 2012;5:2ª.n época. Spanish.; 10. Rogers EM. Diffusion of innovations. 5th ed. New York: Free Press; 2003.; 11. Tang HK. An inventory of organizational innovativeness. Technovation. 1999;19: 41–51.; 16. Dewett T. Employee creativity and the role of risk. Eur. J. Innov. Manag. 2004;7(4): 257–266. 17. Williams SD. Personality, attitude and leader influences on divergent thinking and creativity in organizations. Eur. J. Innov. Manag. 2004;7(3):187–204 . 18. McLean LD. Organizational culture’s influence on creativity and innovation: A review of the literature and implications for human resource development. Adv. Dev. Hum. Resour. 2005;7(2):226–246 . 19. Ellonen R, Blomqvist K, Puumalainen K. The role of trust in organizational innovativeness. Eur. J. Innov. Manag. 2008;11(2):160–181.
Nieboer 2012^20^ | Innovative cultures are known to provide a link between efficient organizational practice and high-quality patient care (Anderson & West, 1998; Mickan & Rodger, 2000; St. John Burch & Anderson, 2003). Innovative culture, conceptualized as group norms that exert control over attitudes and behavior by representing what ‘‘is’’ or ‘‘ought to be’’ in a particular situation may be more or less conducive to creativity, risk taking, and tolerating mistakes and facilitate implementation by generating social approval when working together effectively and acting quickly (Caldwell & O’Reilly, 2003). Such innovative cultures have been reported to enhance the creation and implementation of new ideas and working methods in organizations (Ferlie & Shortell, 2001; Leggat et al., 1998).; Innovation in service delivery and organizations can be defined as a novel set of behaviors, routines, and work methods that improve health outcomes, administrative efficiency, cost effectiveness, or user experience implemented by planned and coordinated actions (Greenhalgh, Robert, Macfarlane, Bate, & Kyriakidou, 2004). Champagne, Denis, Pineault, and Contandriopoulos (1991) and Ferlie and Shortell (2001) have shown that several organizational factors affect an organization’s ability to innovate services. Different organizations provide different contexts for innovation, and some organizational features have been shown to influence the likelihood that an innovation will be successfully assimilated (Greenhalgh et al., 2004).; According to Greenhalgh et al. (2004), leadership styles influence the development of an innovative culture. Den Hartog, Van Muijen, and Koopman (1997) have reported on 3 different management styles: transformational, transactional, and passive. Transactional leaders build expectations by setting specific performance targets with their employees (Avolio & Bass, 1999), significant here because West et al. (2003) have shown that leadership clarity predicts team innovation in health care. Transformational leaders upset the status quo and existing rule structures, replacing them with a ‘‘new order’’ and way of doing things (Ferlie & Shortell, 2001). Passive leaders tend to react only after problems have become serious enough to take corrective action and often avoid making decisions at all (Avolio & Bass, 1999). Transactional and transformational leadership styles are thus expected to be positively related to innovative culture, whereas a passive leadership style is negatively related to innovative culture. | Avolio, B. J., & Bass, B. M. (1999). Re-examining the components of transformational and transactional leadership using the multifactor leadership. Journal of Occupational and Organizational Psychology, 72(4), 441Y462.; Anderson, N. R., & West, M. A. (1998). Measuring climate for work group innovation: Development and validation of the team climate inventory. Journal of Organizational Behavior, 19(3), 235Y258.; Mickan S., & Rodger S. (2000). Characteristics of effective teams: A literature review. Australian Health Review, 23(3), 201Y208.11186055; St. John Burch, G., & Anderson N. (2003). What does it take to be a good team player? Assessing team climate preference can help. Selection and Development Review, 19, 15Y19.; Caldwell, D. F., & O’Reilly, C. A. (2003). The determinants of team-based innovation in organizations: The role of social influence. Small Group Research, 34(4), 497Y517.; Ferlie, E. B., & Shortell, S. M. (2001). Improving the quality of health care in the United Kingdom and the United States: A framework for change. Milbank Quarterly, 79(2), 281Y315.; Leggat, S. G., Narine L., Lemieux-Charles L., Barnsley J., Baker, G. R., Sicotte C., I Bilodeau, H. (1998). A review of organizational performance assessment in health care. Health Services Management Research, 11(1), 3Y18; discussion 19Y23.10178369; Greenhalgh T., Robert G., Macfarlane F., Bate P., & Kyriakidou O. (2004). Diffusion of innovations in service organizations: Systematic review and recommendations. Milbank Quarterly, 82(4), 581Y629.; Champagne F., Denis, J. L., Pineault R., & Contandriopoulos, A. P. (1991). Structural and political models of analysis of the introduction of an innovation in organizations: The case of the change in the method of payment of physicians in long-term care hospitals. Health Services Management Research, 4(2), 94Y111.10115542; Den Hartog, D. N., Van Muijen, J. J., & Koopman, P. L. (1997). Transactional versus transformational leadership: An analysis of the MLQ. Journal of Occupational and Organizational Psychology, 70(1), 19Y34.
Lansisalmi 1999^35^ | Research on the determinants of an innovative climate has concentrated on factors that can be traced back to the classic motivation and organizational behaviour theories, such as goal setting-theory6 and the job characteristics model,7 and 2 management systems based on these theories, total quality management and management by objectives.8–17 On this basis, the role of various correlates of innovative climate, including goal clarity, feedback, communication processes and autonomy, has been explored. | 6. Locke, E. A. and Latham, G. P. A Theory of Goal Setting and Task Performance. Prentice Hall, Englewood-Cliffs, NJ, 1990.; 7. Hackman, J. R. and Oldham G. Work Redesign. Addison-Wesley, Reading, MA, 1980.; 8. Barnard, C. I. Organization and Management. Harvard University Press, Cambridge, 1938.; 9. Drucker, P. F. The Practice of Management. Harper, New York, 1954.; 10. Drucker, P. F. What results should you expect? A user’s guide to MBO. Pub. Admin. Rev. 1976; 36: 12–19.; 11. Drucker, P. F. Innovation and Entrepreneurship: Practice and Principles. Heinemann, London, 1985.; 12. Crosby P. Quality is Free. McGraw-Hill, Washington, DC, 1979.; 13. Juran, J. M. Management of Quality. McGraw-Hill, Washington, DC, 1981.; 14. Deming, W. E. Out of the Crisis: Quality, Productivity and Competitive Position. Cambridge University Press, Cambridge, 1982.; 15. Ishikawa K. What is Total Quality Control. Prentice Hall, Englewood Cli€s, NJ, 1985.; 16. Garvin, D. A. Managing Quality. Free Press, New York, 1988.; 17. Poister, T. H. and Streib G. Management tools in government: Trends over the past decade. Pub. Admin. Rev. 1989; 49: 240–248.
Roen 2018^34^ | Innovative climate construct is mentioned as a domain of the instrument; not explicitly mentioned or defined by authors | Dallner M., Elo A.-L., Gamberale F., Hottinen V., Knardahl S. and Lindström K. (2000). Validation of the General Nordic Questionnaire (QPSNordic) for Psychological and Social Factors at Work. Copenhagen: Nordic Council of Ministers, Nord.
Yan 2020^31^ | Researchers have explored the influence of perceived organizational climate on innovation behaviour, and almost all results support perceived organisational innovation climate as a positive factor in innovation behaviour. Isaksen and Akkermans (2011) mentioned that perceived organisational innovation climate can provide a cognitive foundation for innovation and support the actions to implement innovation. Besides, positive PsyCap can also promote the perceived of the organisational innovation climate. | Qian Y., Zhang Y.-Q., Wu J.-M., & Wang H.-C. (2016). Development and psychometric test of Nurse Organizational Innovation Climate Scale. Chinese Journal of Nursing, 51(02), 243–247.; Isaksen, S. G., & Akkermans, H. J. (2011). Creative climate: A leadership lever for innovation. The Journal of Creative Behavior, 45(3), 161–187.
King 2007^36^ | an organizational climate for innovation can be defined as the extent to which the values and norms of an organization emphasize innovation(West & Anderson, 1996; West & Wallace, 1991). Although little is known about the organizational consequences of climate for innovation, and early investigations of creativity focused on the individual level of analysis (see Amabile, 1996), research has begun to follow a multi-level approach in establishing that innovation is crucial in the long-term survival of organizations (Anacona & Caldwell, 1987; Anderson, de Dreu,&Nijstad, 2004; Drazin, Glynn,&Kazanjian, 1999; Janssen, Van de Vliert, &West, 2004; Oldham & Cummings, 1996). For example, multiple measures of innovation were positively related to organizational effectiveness within the health care industry (West & Anderson, 1996). Damanpour’s (1991) meta-analysis showed that managerial attitudes towards change were determinants of organizational innovation. Similarly, we expect that maintenance of a climate which supports the production and implementation of creative ideas or processes will be related to the performance of organizations.; “In effect, research findings suggest that if the environment of teams is demanding and uncertain, it is likely they will have to innovate successfully in order to reduce the uncertainty and level of demand” (p. 138). (Janssen 2004); Following this theoretical rationale (see also Bunce & West, 1996), we theorize that innovative climates may act as a resource or support function by which employees can manage job demands. | West, M. A., & Farr, J. L. (1990). Innovation and creativity at work: Psychological and organizational strategies. Chichester, England: Wiley.; Gonzalez-Roma V., &West, M. A., (2004). Agreeing to disagree: Climate strength and innovation in work teams. Unpublished manuscript. University of Valencia.; Amabile, T. M. (1988). A model of creativity and innovation in organizations. In B. M. Staw & L. L. Cummings (Eds.), Research in organizations (Vol. 10, pp. 123–167). Greenwich, CT: JAI Press.; West, M. A., & Anderson, N. R. (1996). Innovation in top management teams. Journal of Applied Psychology, 81, 680–693.; West, M. A., & Wallace M. (1991). Innovation in health care teams. European Journal of Social Psychology, 21, 303–315. .; Anacona D., & Caldwell D. (1987). Management issues facing new product teams in high technology companies. In D. Lewin, D. Lipsky, & D. Sokel (Eds.), Advances in industrial and labor relations (Vol. 4, pp. 191–221). Greenwich, CT: JAI Press.; Anderson N., de Dreu, C. K., & Nijstad, B. A. (2004). The routinization of innovation research: A constructively critical review of the state-of-the-science. Journal of Organizational Behavior, 25, 147–173.; Drazin R., Glynn, M. A., & Kazanjian, R. K. (1999). Multilevel theorizing about creativity in organizations: A sensemaking perspective. Academy of Management Review, 24, 286–307.; Janssen O., Van de Vliert, E., & West M. (2004). The bright and dark sides of individual and group innovation: A special issue introduction. Journal of Organizational Behavior, 25, 129–145.; Oldham, G. R., & Cummings A. (1996). Employee creativity: Personal and contextual factors at work. Academy of Management Journal, 39, 607–634.; Damanpour F. (1991). Organizational innovation: A meta-analysis of effects of determinants and moderators. Academy of Management Journal, 14, 555–590.; Bunce D., & West, M. A. (1996). Stress management and innovation interventions at work. Human Relations, 49, 209–222.
Berg 1999^9^ | Ekvall (1996) stated that the organizational climate is important for creativity and innovation among the members of the organization. The organizational climate includes such factors as attitudes, behaviour and feelings that are common in the organization and it exists independently of the perceptions and understandings of the members (Ekvall 1996). | Ekvall G. (1996) Organizational climate for creativity and innovation. European Journal of Work and Organisational Psychology 5, 105–123.
Rashid 2020^32^ | Ekvall (1996) stated that the organizational climate …is important for creativity and innovation among the members of the organization. The organizational climate includes such factors as attitudes, behaviour and feelings that are common in the organization and it exists independently of the perceptions and understandings of the members (Ekvall 1996). The climate of creativity and innovation was measured by the Creative Climate Questionnaire (Ekvall et al. 1983). It has 50 statements covering 10 dimensions of the work climate: challenge, freedom, idea-support, trust, dynamism, playfulness, debates, conflicts (counter indicative), risk-taking and idea-time (Ekvall et al. 1983). The statements are all geared to the capacity of the organization for change and innovation (Ekvall et al. 1987, Ekvall & Tångeberg-Andersson 1986); A low degree of creativity indicates that there is stagnation, and this, in turn, is said to have a negative impact on job satisfaction, well-being, productivity and quality at work (Ekvall 1991).; The degree of creativity among the members of an organization may be the outcome of suitable support systems. Ekvall (1996) stated that the organizational climate is important for creativity and innovation among the members of the organization. The organizational climate includes such factors as attitudes, behaviour and feelings that are common in the organization and it exists independently of the perceptions and understandings of the members (Ekvall 1996). Thus, it seems important to take both intrapersonal and interpersonal factors as well as the actual organizational circumstances into consideration when devising suitable support systems for nurses. | Ekvall G. (1991) Managing Innovation (eds Henry J. & Walker D.), pp. 73–79. Sage Publications, London.; Ekvall G. (1996) Organizational climate for creativity and innovation. European Journal of Work and Organisational Psychology 5, 105–123.; Ekvall G., Arvonen J. & Nyström H. (1987) Organisation and Innovation. Studentlitteratur, Lund.; Ekvall G., Arvonen J. & Waldenström-Lindström I. (1983) Creative Organizational Climate Construction and Validation of a Measuring Instrument, Report 2. FA-rådet, Stockholm.; Ekvall G. & Tångeberg-Andersson Y. (1986) Working climate and creativity. A study of an innovative newspaper office. Journal of Creative Behaviour 3, 215–225.
Jarvis 2017^11^ | …we take creativity to refer to the generation of novel and useful ideas (Amabile et al, 1996) and innovation to relate to the successful implementation of creative ideas to create new value for the organisation and its stakeholders (West and Anderson, 1996). As Isaksen et al (2011:14) claim, “You can have creativity without innovation, but you cannot have innovation without creativity.” This distinction has a particular resonance for our research since the leadership challenge we have uncovered is less about creativity and more about innovation and bringing new ideas, products and processes into practice. It is this translation of creative ideas into innovative products, services and processes that Byrne et al (2009) argue is critical to an organisation’s survival and ability to thrive in an increasingly competitive and complex environment. Tidd and Bessant (2009: 16) suggest “…innovation is a process of turning opportunity into new ideas and of putting these into widely used practice.” Others (eg West and Farr, 1990; Bledow et al, 2009) include intentionality in their definitions, claiming innovation can be defined as: “The intentional introduction and application within a role, group or organisation of ideas, processes, products or procedures, new to the relevant unit of adoption, designed to significantly benefit the individual, the group, organisation or wider society.” (West and Farr, 1990: 9); The innovation literature also focuses on different levels of analysis, from the personal level (e.g Kirton, 1976, 2003), through team level (West, 1990), to whole systems (Csikszentmihalyi, 1988) and the level of society (Simonton, 1999) and addresses them from different perspectives, including social and occupational psychologists, sociologists, management scientists, and organizational behaviourists (King, 1990). It is perhaps not surprising then that the innovation research is characterised by variability of findings (Aasen, 2009).; In this paper our emphasis is on the team level and the role leadership learning can play in facilitating a climate supportive of innovation. In the words of Isaksen (2017: 131), “Creativity is the making and communicating of meaningful new connections and ideas. Innovation is the application and implementation of these insights. Edmondson’s (1999) work in a health setting also stresses the importance of both psychological safety and the quality of relationship and trust between leaders and team members for learning and innovation to take place. These factors influence the way the group works with diversity, and its potential to offer challenge and surprise (Fonseca, 2002), for as West and Hirst (2003: 300) note: …functional or knowledge diversity in the team is associated with innovation.; However, when diversity begins to threaten the group’s safety and integration… Where diversity reduces group members’ clarity about and commitment to group objectives, levels of participation … task orientation … and support for new ideas, then it is likely that innovation attempts will be resisted. | Amabile T.M., Conti R., Coon H., Lazenby J. and Herron M. (1996) ‘Assessing the Work Environment for Creativity’ Academy of Management Journal, 39(5): 1154–1184.; West M.A. and Anderson N.R. (1996) ‘Innovation in Top Management Teams’ Journal of Applied Psychology, 81(6): 680–693.; Isaksen S.G., and Ekvall G. (2007). Assessing the Context for Change: A Technical Manual for the Situational Outlook Questionnaire® - Enhancing Performance of Organizations, Leaders and Teams for Over 50 Years (2nd ed.), Buffalo, NY, USA: The Creative Problem Solving Group, Inc.; Byrne C.L., Mumford M.D., Barrett J.D. and Vessey W.B. (2009). “Examining the Leaders of Creative Efforts: What Do They Do, and What Do They Think About?’ Creativity and Innovation Management 18, (4):256–268.; Tidd J. & Bessant J. (2009) Managing Innovation: Integrating Technological, Market and Organizational Change (4th Ed), Hoboken, NJ: John Wiley & Sons.; West, M. A. and Farr, J. L. (eds) (1990) Innovation and Creativity at Work: Psychological and Organizational Strategies, Chichester: John Wiley.; Bledow R., Frese M., Anderson N., Erez M., & Farr J. (2009) ‘A Dialectic Perspective on Innovation: Conflicting Demands, Multiple Pathways, and Ambidexterity’, Industrial and Organizational Psychology, 2, 305–337.; Kirton M.J. (1976) ‘Adaptors and Innovators: A Description and Measure’, Journal of Applied Psychology, 61: 622–629.; Kirton M.J. (2003) Adaption and Innovation in the Context of Diversity and Change, London: Routledge.; Csikszentmihalyi M. (1990). Flow: The Psychology of Optimal Experience, New York: Harper and Row.; Simonton K. (1999) Origins of Genius: Darwinian Perspectives on Creativity, New York: Oxford Univ Press.; King N. (1990) ‘Innovation at Work: The Research Literature’ in M. West and N. Farr (eds) Innovation and Creativity at Work, pp 15–59, Chichester: Wiley; Aasen T.M.B. (2009) ‘A Complexity Perspective on Innovation Processes for Subsea Technology Development.’ International Journal of Learning and Change, 3(3): 294–307.; Edmondson A. (1999) ‘Psychological Safety and Learning Behavior in Work Teams’ Administrative Science Quarterly, 44: 350–383; Fonseca J. (2002) Complexity and Innovation in Organizations, London: Routledge.; West M.A. and Hirst G. (2003) ‘Co-operation and Teamwork for Innovation’ in M.A. West, D. Tjosvold and K.G. Smith International handbook of Organizational Teamwork and Cooperative Working, Chichester: John Wiley.
Liu 2012^30^ | In this study, we employed the well-established four-factor theory of team climate for innovation proposed by West.(35) This theoretical model identifies 4 essential factors of team climate, participative safety, support for innovation, vision, and task orientation. These factors represent the salient aspects of team climate that have been covered by scholars interested in understanding individuals’ tendencies toward knowledge sharing. A team climate conducive to innovation is characterized as a climate in which individuals are highly trusting of others and of the organization (eg support for innovation), an open climate with free-flowing information and tolerance of well-reasoned failure (eg participatory safety), and a climate infused with pro-social norms (eg vision).(9) | 35. West MA. The social psychology of innovation in groups. In: West MA, Farr JL, eds. Innovation and Creativity at Work: Psychological and Organizational Strategies. Chichester: Wiley, 1990;309–33.; 9. Bock G, Zmud RW, Kim Y, Lee J. Behavioral intention formation in knowledge sharing: examining the role of extrinsic motivators, social-psychological forces, and organizational climate. MIS Quart 2005;29:87–112.
Dackert 2010^33^ | In the present study, West’s model was adopted for the purpose of studying team climate with regard to the innovative processes necessary for improving the quality and efficiency of the care. A study of primary health care teams by Proudfoot et al. (2007) showed a better team climate providing support of innovation to be associated with the patients greater satisfaction with the care they received. In addition, a team climate that supports innovation has been found to be related to psychological well-being among direct care staff in homes for people with intellectual disabilities (Rose et al. 2006).; Based on West’s (1990) model, Anderson and West (1998) examined shared perceptions of team climate in relation to innovative processes; the model consists of 4 dimensions: participation, support for innovation, vision and task orientation. Participation refers to a positive interpersonal atmosphere with ample employee influence, interaction and communication. Support for innovation refers to the degree of encouragement and practical support given to employees attempting to improve their work. Vision comprises 4 components concerning team objectives: clarity, visionary nature, attainability and agreement. Lastly, task orientation refers to the team’s shared concern about the quality of work (West 1990, Anderson & West 1998).; These 4 dimensions have been shown to be related to innovation in teams (Agrell & Gustafson 1994, Anderson & West 1998). Moreover, innovation has been defined as the introduction and application of ideas, procedures, processes etc. within a role, group or organization (West & Farr 1990). | Proudfoot J., Jayasinghe U.W., Holton C. . (2007) Team climate for innovation: what difference does it make in general practice? International Journal for Quality in Health Care 19, 164–169.17337517; Rose J., Ahuja A.P. & Jones C. (2006) Attitudes of direct care staff towards external professionals, team climate and psychological well-being. Journal of Intellectual Disabilities 10, 105–120.16682387; West M.A. (1990) The social psychology of innovation in groups. In Innovation and Creativity at Work. Psychological and Organizational Strategies (M.A. West & J.L. Farr eds), pp.309–333, John Wiley and Sons, Chichester. Anderson N.R. & West M.A. (1998) Measuring climate for work group innovation: Development and validation of the team climate inventory. Journal of Organizational Behavior 19, 235–258.
Proudfoot 2007^25^ | Collaborative teamwork provides a link between efficient organizational practice and high-quality patient care [1], with the team’s ability to be innovative as 1 hypothesized mechanism.; Innovative teams are characterized by high levels of support and challenge, sharing and implementing new ideas and clarity of tasks and objectives [2]. Four team processes have been shown to be important: having clearly defined and valued group goals, participative decision-making, quality task orientation and support for innovation [3]. When these 4 factors are present, innovativeness and effectiveness are higher [4].; Innovative team processes are also associated with better quality care for patients and with team members’ well-being and satisfaction…Specifically, teams that had clear, shared objectives were task-focused with an emphasis on quality, participated in decision making and open to innovation were more likely to work well as a team, structure their work more effectively and to be more effective in their health care delivery. | 1. Mickan S, Rodger S. The organisational context for teamwork: comparing health care and business literature. Aust Health Rev 2000;23:179–92.10947601; 2. Guzzo R, Shea G. Group performance intergroup relations in organisations. In: Dunnette M, Hough L (eds). Handbook of Industrial and Organisational Psychology. Palo Alto, CA: Consulting Psychologists Press, 1992, pp. 269–313.; 3. Anderson N, West M. Measuring climate for work group innovation: development and validation of the team climate inventory. J Org Behav 1998;19:235–58.; 4. St John Burch G, Anderson N. What does it take to be a good team player? Assessing team climate preference can help. Select Dev Rev 2003;19:15–19.
Anderson 1998^26^ | …work group innovation as being the facet-specific construct of interest in the present study. West and Farr, (1989) define innovation as ‘the intentional introduction and application within a role, group or organization of ideas, processes, products or procedures, new to the relevant unit of adoption, designed to significantly benefit role performance, the group, the organization or the wider society’ (p. 16). Comparatively few studies have focused at the level-of-analysis of the work group. This is a notable shortcoming since it is often the case that an innovation is originated and subsequently developed by a team into routinized practice within organizations (West and Farr, 1990; Anderson and King, 1993; King and Anderson, 1995).; ‘… the expectation, approval and practical support of attempts to introduce new and improved ways of doing things in the work environment’ (West, 1990, p. 38). Support for innovation varies across teams to the extent that it is both articulated and enacted. West argues that articulated support, by implication, may be found in personnel documents, policy statements, or conveyed by word of mouth. It is argued that a necessary condition for group innovation is enacted support, as opposed to merely articulated support, whereby active support is provided for innovatory behaviour. Daft (1986), for instance, found that resources needed to be made available to develop innovations, whilst Schroeder, Van de Ven, Scrudder and Polley (1989) stressed the importance of support from the power elite for innovation implementation. | Siegel, S. M. and Kaemmerer, W. F. (1978). ‘Measuring the perceived support for innovation in organizations’, Journal of Applied Psychology, 63, 553–562.; West, M. A. (1990). ‘The social psychology of innovation in groups’. In: West, M. A. and Farr, J. L. (Eds) Innovation and Creativity at Work: Psychological and Organizational Strategies, Wiley, Chichester, pp. 4–36.; West, M. A. and Farr, J. L. (1989). ‘Innovation at work: psychological perspectives’, Social Behaviour, 4, 15–30.; West, M. A. and Farr, J. L. (Eds) (1990). Innovation and Creativity at Work: Psychological and Organizational Strategies, Wiley, Chichester.; King N. and Anderson, N. R. (1995). Innovation and Change in Organizations, Routledge, London.; Anderson, N. R. and King N. (1993). Innovation in Organizations. In: Cooper, C. L. and Robertson, I. T. (Eds) International Review of Industrial Organizational Psychology, Vol. 8, Wiley, Chichester, pp. 1–33.; Daft, R. L. (1986). ‘A dual-core model of organization innovation’, Academy of Management Journal,21,193–210.; Schroeder, R. G., Van de Ven, A. H., Scrudder, G. D. and Polley D. (1989). ‘The development of innovation ideas’. In: Van de Ven, A. H., Angle, H. L. and Poole, M. S. (Eds) Research on the Management of Innovation: The Minnesota Studies, Harper & Row, New York,pp.107–134.
Bunce 1995^10^ | The influence of groups in determining at the outset the extent to which an individual’s ideas for innovations are translated into practical action or rejected can therefore be considerable. There is certainly evidence that group climate factors have an important influence on work-group innovation (Anderson & West, 1992; West & Anderson, 1994; West & Wallace, 1992) and good reason for supposing that group climate will influence individual innovation attempts; 4. Support for Innovation; This is defined (West, 1990, p.38) as “The expectation, approval, and practical support of attempts to introduce new and improved ways of doing things in the work environment”. Support for innovation vanes across teams to the extent that it is both articulated and enacted. West argues that articulated norms, by implication, may be found in personnel documents, or in policy statements, or conveyed by word of mouth. It is argued that a necessary condition for group innovation is enacted norms, as opposed to merely articulated norms whereby active support is provided for innovative behaviour-somewhat similar to Argyris’ (1993a, b) distinction between espoused theories and theories in use.; Propensity to Innovate… explored respondents’ attitudes towards seeking out new and improved ways of working and was derived from an original 12-item scale (Burningham & West, 1995). | Anderson. N.R., & West M.A. (1992). Team climate for innovation. Memo Number 1430.; Burningham C., & West. M.A. (1995). Individual, climate, and group interaction processes as predictions of work team innovation. Small Group Research, 26.; West M.A.. & Anderson N.R. (1994). Predicting innovation in team at work: A test of the theory of group innovation. Unpublished manuscript. Memo No. 1308. MRCESRC Social and Applied Psychology Unit, University of Sheffield, UK.; West M.A., & Wallace M. (1992). Innovation in health care teams. European Journal of Social Psychology, 21, 303–31s.; West M.A. (1990). The social psychology of innovation in groups. In M.A. West & J.L. Farr (Eds.), Innovation and creativity at work: Psychological and organizational strategies. Chichester, UK: Wiley.; Argyris C. (1993a). On the nature of actionable knowledge. The Psychologist, 6(1), 29–32.
West 1991^39^ | West and Farr (1989) argue, in a review of the literature, that innovative groups will be cohesive, have participative leadership, strong norms for innovation in the team climate, a focus on both rational and intuitive thinking, and a concern with quality of task performance. The individuals comprising such groups, they suggest, will have a high propensity to innovate and task appropriate skills. Similarly, both Kanter (1983) and Peters and Waterman (1982) suggest that innovation is most likely to occur where the leadership style is collaborative and participative. | West, M. A. and Farr, J. L. (1989). ‘Innovation at work, Psychological perspectives’, Social Behaviour, 4: 15–30.; Kanter R. (1983). The Change Masters, Simon and Schuster, London.; Peters, T. J. and Waterman, R. H. (1982). In Search of Excellence. Lessons from America’s Best Run Companies, Harper and Row, New York.
Weng 2015^18^ | Employee innovation behaviour is influenced by the organisational climate that is perceived by employees. When the organisational behaviour climate is supportive of employee innovation behaviours, the employees are more willing to transform their creative ideas into innovative outputs (Weng et al. 2012a). Jong and Vermeulen (2003) identified that organisational climate is a critical factor to carry out new service development effectively. However, there are often various aspects of organisational climate existing at the same time in an organisation. Recently, for improving care quality, patient safety climate has already become a key management point in healthcare organisations (Hughes et al. 2009). In addition, a good innovation climate in organisations will provide the employees with resources, as well as technical and psychological support, to create a positive attitude toward innovation, and thus, enhance employee innovation performance (Sarros et al. 2008, Dackert 2010). This study defines innovation behaviour as a process during which nurses reinforce the generation, establishment, evaluation and implementation of creative ideas. Healthcare innovation is about doing things differently or doing different things to achieve large gains in performance (McSherry & Douglas 2011). Nurse innovation behaviours cover the areas of research, clinical practices, management, education, technologies, public health and policies (Hughes 2006). Innovation in nursing practice could be seen as the encouragement of professionals to utilise their acquired knowledge and skills in order to generate and develop new ways of working creatively and drawing on technologies, systems, theories and associated partners/stakeholders that may further enhance and evaluate nursing practice (McSherry & Douglas 2011). For nurses, innovation refers to eliminating old care or improving existing care in order to develop new behaviours (Holleman et al. 2009); innovation behaviours refer to the degree of nurses’ participation in work improvement, inviting others to participate, and nurses’ adoption of the work improvement plan (_Amo 2006). According to Blakeney et al. (2009) nursing innovation is a process that brings creativity to measurable outcomes, actions, products or processes. Knol and van Linge (2009) argued that the generation, implementation and achievement of creative ideas, as well as the acceptance of innovation outcomes and seeking the support of others on innovation activities, are all essential for nursing innovation. | Weng R.H., Huang C.Y., Huang J.A. & Wang M.H. (2012a) The cross-level impact of patient safety climate on nursing innovation: a cross-sectional questionnaire survey. Journal of Clinical Nursing 21 (15–16), 2262–2274.22788560; Jeong S.Y. & Keatinge D. (2004) Innovative leadership and management in a nursing home. Journal of Nursing Management 12 (6), 445–451.15509274; Hughes L.C., Chang Y. & Mark B.A. (2009) Quality andstrength of patient safety climate on medical-surgical units. Health Care Management Review 34 (1), 19–28.19104261; Sarros J.C., Cooper B.K. & Santora J.C. (2008) Building a climate for innovation through transformational leadership and organizational culture. Journal of Leadership and Organizational Studies 15 (2), 145–158.; Dackert I. (2010) The impact of team climate for innovation on well-being and stress in elderly care. Journal of Nursing Management 18 (3), 302–310.20546470; McSherry R. & Douglas M. (2011) Innovation in nursing practice: a means to tackling the global challenges facing nurses, midwives and nurse leaders and managers in the future. Journal of Nursing Management 19 (2), 165–169.21375618; Hughes F. (2006) Nurses at the forefront of innovation. International Nursing Review 53 (2), 94–101.16650027; Holleman G., Poot E., Groot J.M.-D. & Achterberg T.V. (2009) The relevance of team characteristics and team directed strategies in the implementation of nursing innovations: a literature review. International Journal of Nursing Studies 46 (9), 1256–1264.19371873; _Amo B.W. (2006) Employee innovation behaviour in health care: the influence from management and colleagues. International Nursing Review 53 (3), 231–237.16879187; Blakeney B., Carleton P., McCarthy C. & Coakley E. (2009) Unlocking the power of innovation. OJIN: The Online Journal of Issues in Nursing 14 (2), 1–12.; Knol J. & van Linge R. (2009) Innovative behaviour: the effect of structural and psychological empowerment on nurses. Journal of Advanced Nursing 65 (2), 359–370.19191936
Nazir 2018^12^ | According to West et al. [1], organizations rely on employees’ innovative behavior [IB] to enhance efficiency and productivity, which in turn ensures continuous organizational growth, success, and survival [2–5]. Innovative behavior results in the generation of a new idea, effective multitasking procedures, and increases job-related motivation [6]. Martins & Terblanche [7] argues that organizations invest a significant amount of time and money to enhance the employee innovative behavior.; Innovative behavior generates new ideas, including effective multitasking processes and job-related managerial motivation [6]. In order to organize the innovation process, firms take into consideration the various actors that assist them in the development of employees’ IB [7], and employees are expected to improve their organization’s processes by producing and implementing innovative solutions that enhance both customer satisfaction and services [8].; McLean [44] defines IB as the creation of novel solutions and valuable ideas in different fields, while innovation refers to the effective execution of these novel solutions in the organization [44]. In other words, IB is known as the process of providing novel ideas to solve problems in organizational practice [45,46]. Jafri [46] proposes that knowledge can be utilized to stimulate novel ideas, which may, in turn, be applied to deliver enhanced customer service and solve problems creatively. It is argued that individual IB and the collective capacity of knowledge workers boosts innovation in organizations [47]. IB involves an improved way of performing tasks through a combination of new notions, processes, products, and services that are (a) unique, and (b) beneficial for the organization [6,48,49].; Such creative ideas can come from employees at any level or in any job within the organization and not only those jobs that usually demand IB [50,51]. Innovative behavior results in enhancing efficiency and effectiveness of employees and is generally considered to be an outcome of the interaction between innovative workers. However, Subramaniam & Youndt [52] emphasized that innovation is a management process that requires both managerial and organizational support. Similarly, Scott & Bruce [3] propose that IB requires a conducive organizational environment that consists of appropriate supervision and social relations at the workplace. These arguments are consistent with the characteristics of social exchange theory (SET). SET proposes that none of this can take place without the appropriate organizational support when employees recognize that their organization and supervisor are fair and supportive that ultimately develops an organizational culture, which supports and enhances IB [32,53,54]. | 1. West M.A.; Hirst G.; Richter A.; Shipton H. Twelve steps to heaven: Successfully managing change through developing innovative teams. Eur. J. Work Organ. Psychol. 2004, 13, 269–299.; 2. Oldham G.R.; Cummings A. Employee creativity: Personal and contextual factors at work. Acad. Manag. J. 1996, 39, 607–634.; 3. Scott S.G.; Bruce R.A. Determinants of innovative behavior: A path model of individual innovation in the workplace. Acad. Manag. J. 1994, 37, 580–607.; 4. Shalley C.E. Effects of coaction, expected evaluation, and goal setting on creativity and productivity. Acad. Manag. J. 1995, 38, 483–503.; 5. Woodman R.W.; Sawyer J.E.; Griffin R.W. Toward a theory of organizational creativity. Acad. Manag. Rev. 1993, 18, 293–321.; 6. Amabile T.M.; Conti R.; Coon H.; Lazenby J.; Herron M. Assessing the work environment for creativity. Acad. Manag. J. 1996, 39, 1154–1184.; 7. Martins E.; Terblanche F. Building organisational culture that stimulates creativity and innovation. Eur. J. Innov. Manag. 2003, 6, 64–74.; 8. Dean A.; Kretschmer M. Can ideas be capital? Factors of production in the postindustrial economy: A review and critique. Acad. Manag. Rev. 2007, 32, 573–594.; 35. Sarooghi H.; Libaers D.; Burkemper A. Examining the relationship between creativity and innovation: A meta-analysis of organizational, cultural, and environmental factors. J. Bus. Ventur. 2015, 30, 714–731.; 36. Chua R.Y.; Roth Y.; Lemoine J.-F. The impact of culture on creativity: How cultural tightness and cultural distance affect global innovation crowdsourcing work. Adm. Sci. Q. 2015, 60, 189–227.; 44. McLean L.D. Organizational culture’s influence on creativity and innovation: A review of the literature and implications for human resource development. Adv. Dev. Hum. Resour. 2005, 7, 226–246.; 46. Jafri M.H. Organizational commitment and employee’s innovative behavior. J. Manag. Res. 2010, 10, 62–68.; 47. Xerri M. Workplace relationships and the innovative behaviour of nursing employees: A social exchange perspective. Asia Pac. J. Hum. Resour. 2013, 51, 103–123.; 48. Shalley C.E.; Zhou J.; Oldham G.R. The effects of personal and contextual characteristics on creativity: Where should we go from here? J. Manag. 2004,30, 933–958.; 49. Zhou J.; George J.M. When job dissatisfaction leads to creativity: Encouraging the expression of voice. Acad. Manag. J. 2001, 44, 682–696.; 50. Madjar N.; Oldham G.R.; Pratt M.G. There’s no place like home? The contributions of work and nonwork creativity support to employees’ creative performance. Acad. Manag. J. 2002, 45, 757–767.; 51. Nonaka I. The knowledge-creating company. Harv. Bus. Rev. 1991, 69, 96–104.; 52. Subramaniam M.; Youndt M.A. The influence of intellectual capital on the types of innovative capabilities. Acad. Manag. J. 2005, 48, 450–463.; 53. Åmo B. Employee innovation behaviour in health care: The influence from management and colleagues. Int. Nurs. Rev. 2006, 53, 231–237.16879187; 54. Cropanzano R.; Prehar C.A.; Chen P.Y. Using social exchange theory to distinguish procedural from interactional justice. Group Organ. Manag. 2002, 27, 324–351.
Sommez 2019^38^ | Innovative behavior (IB) is defined as all individual activities pertaining to the development, promotion and implementation of a useful innovation at any organizational level (Rank et al., 2004; Moisio et al., 2007). IB includes the development of new ideas, technology and techniques, as well as the trial and application of new methods related to business procedures in specific work areas (Moisio et al., 2007). Studies have emphasized the importance of developing IB in healthcare professionals to ensure that healthcare institutions are able to deliver rapid, reliable and high-quality patient care (Reuver et al., 2008; Xerri and Brunetto, 2012). IB practiced by healthcare professionals has been shown to be significant for improving patient outcomes and organizational performance (Bunpin et al., 2016).; There have been various studies conducted over the last decade investigating the factors responsible for developing IB in nurses (Knol and van Linge, 2009; Xerri and Brunetto, 2012; Xerri, 2013; Sönmez and Yıldırım, 2014; Koyuncu, 2015; Afsar and Masood, 2018; Afsar et al., 2018). These studies have revealed that the IB of nurses was associated with structural and psychological empowerment, interactional justice, perceived organizational support, leader–member exchange and person-organization fit (Knol and van Linge, 2009; Xerri and Brunetto, 2012; Afsar et al., 2018). In addition to these, supervisor supportiveness (SS) and autonomy have also been found to be important factors affecting the development of IB in nurses (Sönmez and Yıldırım, 2014). In a study conducted with physicians and nurses, the tendency toward IB and transformational leadership was determined to increase in line with certain personality traits, such as extraversion, agreeableness, self-discipline and emotional balance (Koyuncu, 2015). One of the organizational factors affecting innovation is organizational climate. It has been stated that to foster innovation, it is particularly important to create an organizational climate that is non-threatening psychologically, supports risk-taking and motivates the employees to apply initiative (Parzafall et al., 2008). It has also been emphasized that organizational support and SS, when perceived to be fair by employees, will improve IB (Xerri and Brunetto, 2012). Furthermore, 1 study has shown that organizational climate needs to include certain characteristics, such as team cohesion, SS, and autonomy, to foster the IB of employees (Balkar, 2015).; A number of studies have investigated the correlation between organizational climate – 1 that supports innovation – creativity and IB (Scott and Bruce, 1994; Yu et al., 2013; Balkar, 2015; Shanker et al., 2017). For example, in the study by Scott and Bruce (1994) on this subject, they highlighted the necessity of having an organizational climate that supports IB and provides necessary resources, 2 qualification that serve as the basis of IB literature. In the qualitative study by De Jong and Den Hartog (2007), managers stated that the innovative climate of the organization was the precursor to employees’ IB. Yu et al. (2013), in their study, reported there to be a positive correlation between knowledge sharing and IB and between a pro-innovation organizational climate and IB. Furthermore, Shanker et al. (2017), in their study, revealed that the innovative climate of an organization improves IB. Four factors help to facilitate the structural empowerment of employees, namely, opportunity, knowledge, support and organizational resources. Nurses who are highly empowered have been identified to display more IB (Knol and van Linge, 2009). In a study by Xerri (2013), the mediating role of perceived organizational support that lies between leader–member exchange and the IB of nurses was described.; There is a consensus on the view that nurses are creative in finding solutions to problems involving healthcare services and patient care (Gillmartin, 1999). Management support hasbeen shown to significantly contribute to transforming employees’ creative ideas into marketable innovations (Parzafall et al., 2008).; IB has also often been studied in correspondence with the leadership styles of managers (Scott and Bruce, 1994; Wilson-Evered et al., 2001; Afsar and Masood, 2018). One of the work-related factors affecting IB is autonomy. Autonomy is stated to be 1 of the main antecedents of IB (De Spiegelaere et al., 2014). | Rank J., Pace V.L. and Frese M. (2004), “Three avenues for future research on creativity, innovation, and initiative”, Applied Psychology: An International Review, Vol. 53 No. 4, pp. 518–528.; Moisio E., Lempiälä T. and Nylander M. (2007), “Invention rewards and innovativeness – a case study”, RMC, Brussels.; Reuver M., Van Engen, M.L., Vinkenburg C.L. and Wilson-Evered E. (2008), “Transformational leadership and innovative work behaviour: exploring the relevance of gender differences”, Creativity and Innovation Management, Vol. 17 No. 3, pp. 227–243.; Xerri M. (2013), “Workplace relationships and the innovative behaviour of nursing employees: a social exchange perspective”, Asia Pacific Journal of Human Resources, Vol. 51 No. 1, pp. 103–123.; Bunpin J.J., Chapman S., Blegen M. and Spetz J. (2016), “Differences in innovative behavior among hospital-based registered nurses”, The Journal of Nursing Administration, Vol. 46 No. 3, pp. 122–127.26866324; Knol J. and Van Linge, R. (2009), “Innovative behavior: the effect of structural and psychological empowerment on nurses”, Journal of Advanced Nursing, Vol. 65 No. 2, pp. 359–370.19191936; Xerri M.J. and Brunetto Y. (2012), “Social exchange and innovative behaviour of nursing employees: A hierarchical linear examination”.; Afsar B., Cheema S. and Bin Saeed, B. (2018), “Do nurses display innovative work behavior when their values match with hospitals’ values?”, Europan Journal of Innovation Management, Vol. 21, No. 1, pp. 157–171.; Sönmez B. and Yıldırım A. (2014), “Determination of nurses’ innovative behaviours and their views about the factors affecting their innovative behaviours: a qualitative study in a university hospital”, Journal of Health and Nursing Management, Vol. 1 No. 2, pp.49–59.(in Turkish).; Koyuncu A.G. (2015), “Hastanelerde örgütsel yenilik: doktor ve hemşireler ile yapılan bir çalışma (Organisational innovation in hospitals: a study conducted for doctors and nurses)”, HAK-İŞ Uluslararası Emek ve Toplum Dergisi, Vol. 4 No. 9, pp. 181–197 (in Turkish).; Parzafall M., Seeck H. and Leppänen A. (2008), “Employee innovativeness in organizations: a review”, LTA, Vol. 2 No. 8, pp. 165–182.; Balkar B. (2015), “The relationships between organizational climate, innovative behavior and job performance of teachers”, International Online Journal of Educational Sciences, Vol. 7 No. 2, pp. 81–92.; Scott S.G. and Bruce R.A. (1994), “Determinants of innovative behavior: a path model of individual innovation in the workplace”, Academy of Management Journal, Vol. 37 No. 3, pp. 580–607.; Yu C., Yu T.-F. and Yu C.-C. (2013), “Knowledge sharing, organizational climate, and innovative behavior: a cross-level analysis of effects”, Social Behavior and Personality, Vol. 41 No. 1, pp. 143–156.; De Jong, J.P.J. and Den Hartog, D.N. (2007), “How leaders influence employees’ innovative behaviour”, European Journal of Innovation Management, Vol. 10 No. 1, pp. 41–64.; Gillmartin M.J. (1999), “Creativity: the fuel of innovation”, Nurse Administration Quarterly, Vol. 23 No. 2, pp. 1–8.; Wilson-Evered E., Härtel C.E.J. and Neale M. (2001), “A longitudinal study of work group innovation: the importance of transformational leadership and morale”, Advances in Health Care Management, Vol. 2, pp. 315–340.; Afsar B., Cheema S. and Bin Saeed, B. (2018), “Do nurses display innovative work behavior when their values match with hospitals’ values?”, Europan Journal of Innovation Management, Vol. 21, No. 1, pp. 157–171.; De Spiegelaere, S., Van Gyes, G., De Witte, H., Niesen W. and Van Hootegem, G. (2014), “On the relation of job insecurity, job autonomy, innovative work behaviour and the mediating effect of work engagement”, Creativity and Innovation Management, Vol. 23 No. 3, pp. 318–330.
Kim 2015^19^ | Innovative behaviors occur when members of an organization generate new ideas and apply them to specific activities to improve individual and organizational achievement.3,10,11 Innovative behaviors are influenced by the personal characteristics of the members as well as organizational characteristics such as its atmosphere, structure, and culture.3 Individual innovative behavior is initiated, and then the innovation of a team or organization is implemented through a mutual network and member communication.12 Self leadership and individual voluntary efforts affect creativity and innovative behaviors13 and can lead to a strong sense of accomplishment with regard to work and activities.14 Creative self-efficacy is defined as confidence in one’s ability and includes creative problem-solving based on the situation.15; Individuals with high creative self-efficacy are more likely to be able to successfully perform a particular task and can more efficiently mobilize the cognitive resources, motivation, and activities needed to meet the situation.16 Knowledge sharing is important for the knowledge-based management process of the organization; it plays an important role in exhibiting innovative behaviors and is relatively effective when knowledge is shared and exchanged within the organization.17 An innovative organizational culture is formed, and the thinking, attitudes, and behavior of its members become more innovative.18,19 In other words, members are more likely to behave in innovative ways because the organization motivates these behaviors by supporting the generation of new ideas and forming a culture in which the ideas can be actively used.20; The innovative behavior model21 asserts that individual attributes, team-member exchanges, and leader member exchanges directly and indirectly influence individual innovative behaviors through social and psychological environments. The innovation-creativity environment model12 states that creativity is closely related to the organizational environment and emphasizes that innovation occurs within a team and organization through member interactions as a result of individual creativity.; …self-leadership was considered an individual attribute, individual knowledge sharing was considered a team-member exchange, and organizational knowledge sharing was considered a leader-member exchange. Three variables evaluated the effect on individual innovative behavior through creative self-efficacy and innovative organizational culture (Figure 1). Self-leadership is an important factor that affects innovative behavior,14 and creativity self efficacy 22,23 causes a strong sense of accomplishment in helping to perform duties. Individual knowledge sharing plays an important role in the realization of creative self-efficacy and individual innovation behavior, 11 as well as improves the quality of the relationships among team members.21 Individuals with creative self-efficacy successfully generate innovation as a result of mobilizing activities, motivation, and human resources.16 Organizational knowledge sharing plays an important role in demonstrating the creativity of an organization as well as creates organizational competency through the exchange and expansion of knowledge between members.24,25; Innovative organizational culture plays an important role in generating human resource innovation and stimulating innovative activities by adjusting the work environment.18 The innovation of an organization exists through individual innovative behaviors because the individual accepts and interprets the idea, and the organization adopts the breakthrough innovation.5,6 | Kim DW. A research on the relationship between core self evaluations and innovative behavior intentions with self leadership as a mediator in the small-medium sized healthcare organizations. Health Soc Welfare Rev. 2014;34(1):408–435.; 10. Song JS, Yang PS. A study on mediating effects of organizational commitment on the relationships between self-leadership and innovative behavior. Korean Corp Manage Rev. 2008; 15(1):189–209.; 11. De Jong K, Den Hartog D. Measuring innovative work behavior. Creat Innov Manage. 2010;19(1):23–26.; 12. Blakeney BA, Carleton RF, McCarthy C, Coakley E. Unlocking the power of innovation. Online J Issues Nurs. 2009;14(2).; 14. Carmeli A, Meitar R, Weisberg J. Self-leadership skills and innovative behavior at work. Int J Manpower. 2006;27(1):75–90.; 15. Tierney P, Farmer SM. Creative self-efficacy development and creative performance over time. J Appl Psychol. 2011;96(2): 277–293.20954756; 16. Michael LA, Sheng TH, Hsueh LF. Creative self-efficacy and innovative behavior in a service setting: optimism as a moderator. J Creat Behav. 2011;45(4):258–272.; 17. Mura M, Lettieri E, Radaelli G, Spiller N. Promoting professionals innovative behaviour through knowledge sharing: the moderating role of social capital. J Knowl Manage. 2013;17(4):527–544.; 18. Kwon JS. The influence of innovative organization culture to human resource innovation and organizational commitment. J Bus Res. 2011;23(1):153–182.; 19. Chang JC, Yang YL. The effect of organization’s innovational climate on student’s creative self-efficacy and innovative behavior.Bus Entrepreneur J. 2012;1(1):75–100.; 20. Kim IC, Kim JW, Lee JW. Determinants of innovative work behavior. J Bus Res. 2004;19(2):282–317.; 21. Scott SG, Bruce RA. Determinants of innovative behavior: a path model of individual innovation in the workplace. Acad Manage J. 1994;37(3):580–607.; 22. Mansor A, Darus A, Dali MH. Mediating effect of self-efficacy on self-leadership and teachers_organizational citizenship behavior behavior: a conceptual framework. Int J Econ Bus Manage Stud. 2013;2(1):1–11.; 23. Masood K, Shahzad C, Nosheen R, Awais K. Effects of self leadership, knowledge management and culture on creativity. Eur J Bus Manage. 2011;3(8):1–12.; 24. Moon IO. The effect of knowledge sharing on innovative behavior and organizational commitment in clinical nurses. J Korean Acad Nurs Adm.2005;11(2):173–183.; 25. Richter AW, Hirst G, van Knippenberg D, Baer M. Creative self-efficacy and individual creativity in team contexts: cross level interactions with team informational resources. J Appl Psychol. 2012;97(6):1282–1290 22800186 .; 5. Ko DY, Yoo TY. The effect of job autonomy on innovation behavior: the mediating effect of job satisfaction and moderating effects of personality and climate for innovation. Korean J Ind Organ Psychol. 2012;25(1):215–238.; 6. Shim DS, Ha SW. A study on the relationship between job characteristics and innovative behavior: the mediating effect of self-efficacy. Korean J Ind Res. 2013;9:95–124.C
Weng 2012^37^ | Nursing innovation not only contributes to enhancing the quality of healthcare but also facilitates nursing productivity (Moody 2004, Chang & Liu 2008).; Innovation is viewed as a multistage process. The entire process includes generating ideas, building coalitions, realizing ideas and innovation diffusion (Scott & Bruce 1994, Rogers 1995). Employee innovation behaviour is the conduct and performance of employees striving to achieve new levels of improvement, as well as the innovative activities revealed after experiencing multiple stages of progress (Hofmann & Mark 2006, Chang & Liu 2008). For nurses, nursing innovation refers to nurses improving nursing quality, inviting people alike to participate, using improvement programs and developing novel nursing behaviour (Amo 2006, Holleman et al. 2009). Specifically, innovation is the motivation and cognitive process derived from a desire to improve tasks. Apart from generating, processing and realising creativity, innovation also includes accepting new concepts and seeking the support and cooperation from others to implement novel activities or technologies (van der Weide & Smits 2004, Kotwal 2005). In addition to realising knowledge creation, integrating innovation into daily nursing routines is an imperative. Hansen and Birkinshaw (2007) indicated that the value of in-house innovation comprises generating, transforming and diffusing opinions. Thus, all 3 types of innovative dimensions must be accounted for when investigating nursing innovation. This study believes that in-house creativity is generated through the creation of knowledge among employees (Smith et al. 2005). Creative transformation involving new knowledge can result in innovative behaviour. If employee innovation behaviour is affirmed by colleagues, superiors and subordinates, this behaviour is likely to diffuse. | Amo BW (2006) Employee innovation behaviour in health care: the influence from management and colleagues. International Nursing Review 53, 231–237.16879187; Chang L & Liu C (2008) Employee empowerment, innovative behavior and job productivity of public health nurses: a cross-sectional questionnaire survey. International Journal of Nursing Studies 45, 14–42.17512527; Moody RC (2004) Nurse productivity measures for the 21st century. Health Care Management Review 29, 7–19.; Rogers EM (1995) Diffusion of Innovations, 4th edn. Free Press, New York, NY.; Scott SG & Bruce RA (1994) Determinates of innovative behavior: a path model of individual innovation in the workplace. Academy of Management Journal 37, 580–607.; Hofmann DA & Mark B (2006) An investigation of the relationship between safety climate and medication errors as well as other nurse and patient outcomes. Personnel Psychology 59, 847–869.; Holleman G, Poot E, Mintjes-de Groot J & van Achterberg T (2009) The relevance of team characteristics and team directed strategies in the implementation of nursing innovations: a literature review. International Journal of Nursing Studies 46, 1256–1264.19371873; van der Weide M & Smits J (2004) Adoption of innovations by specialised nurses: personal, work and organizational characteristics. Health Policy 68, 81–92.15033555; Kotwal A (2005) Innovation, diffusion and safety of a medical technology: a review of the literature on injection practices. Social Science & Medicine 60, 1133–1147.15589680; Smith KG, Collins GJ & Clark KD (2005) Existing knowledge, knowledge creation capability, and the rate of new product introduction in high-technology firms. Academy of Management Journal 48, 346–357.; Hansen MT & Birkinshaw J (2007) The innovation value chain. Harvard Business Review 85, 121–130.
Acar 2012^23^ | Adhocracy (creative) culture with its external-oriented and dynamic structure refers to the culture of an organization in entrepreneurial, flexible, innovative and creative areas. Employees can take the initiative, supported with new discoveries and freedoms so they feel satisfied, happy and successful in this environment (Berrio, 2003, Cameron & Quinn, 1999; Erdem, 2007).; Innovativeness is the measure of the degree of newness of an innovation. According to the literature most seen classification of innovativeness is product and process innovation. In current research, in order to measure organizational innovation, 18-item Likert scales of Wang and Ahmed (2004) and Jansen et. al. (2006) is given to the participants. | Berrio A.A. (2003) An organizational culture assessment using the competing values framework: A profile of Ohio State Unive Journal of Extension, 41(2).; Jansen J.J.P., Van Den Bosch, F.A.J., and Volberda H.W. (2006). Exploratory innovation, exploitative innovation, and performance: Effects of organizational antecedents and environmental moderators. Management Science, 52(11), 1661–1674.; Wang C.L., and Ahmed P.K. (2004). The development and validation of the organisational innovativeness construct using confirmatory factor analysis. European Journal of Innovation Management, 7(4), 303–313.; Cameron K.S., and Quinn R.E. (1999). Diagnosing and changing organizational culture: Based on the competing values framework. Reading, MA: Addison-Wesley.
Mesfin 2020^22^ | A major goal of the adhocracy culture is to foster adaptability, flexibility, and creativity where uncertainty, ambiguity, and information overload are typical. An important challenge for these organizations is to produce innovative products and services and to adapt quickly to new opportunities. | Cameron KS, Quinn RE. Diagnosing and changing organizational culture:based on the competing value framework. New York: Wiley; 2012.
Gozukara 2019^14^ | Development culture is a type of organisational culture that fosters employee motivation, especially regarding learning processes (Scott, Mannion, Marshall, & Davies, 2003). The important factors in this culture include growth, encouragement, creativity and diversification. Development culture involves and empowers significant values and attitudes directly related with the work of employees (Akkoc¸, C¸ alıs¸kan, & Turunc, 2012). Thus, it provides more focus and stability in terms of identifying and setting ground for such values. It also enables flexibility with a focus on external environment. The orientation of this culture is towards improvement, innovation and continuous adaptation to changing environment. Therefore, organisations with a development culture are likely to strive for meeting their customers’ expectations through constant innovative activities (Elfaituri, 2012). | Scott T., Mannion R., Marshall M., & Davies H. (2003). Does organizational culture influence healthcare performance? A review of the evidence. Journal of Health Services Research and Policy, 8(2), 105–117.12820673; Akkoc¸ I˙, C¸ alı s¸kan, A., & Turunc¸ O¨. (2012). O¨ rgu¨tlerde gelis¸im ku¨ltu¨ru¨ ve algılanan o¨rgu¨tsel desteg˘in is¸ tatmini ve is¸ performansına etkisi: Gu¨venin aracı rolu¨. Yo¨netim ve Ekonomi, 19(1), 105–135.; Elfaituri, A. A. (2012). An assessment of TQM implementation, and the influence of organizational culture on TQM implementation in Libyan banks (PhD thesis). University of Gloucestershire.
Chan 2008^50^ | Adopting a human- and innovation- oriented culture, which allows employees to solve problems and learn to improve from mistakes, will be perceived by employees as benevolent support which is then translated into trust. This convinces employees to exercise their self-determination and enhances their competency to freely experiment with learning new ways to do things without fear of being unfairly penalized. Employees confidently seek to gain better control and power in their work environment through trusting their supervisors, thus enabling them to get involved in contributing to the overall achievement of organization goals. Such acts contribute to employees’ perception of supervisors’ integrity and depend-ability.; Four major positive characteristics of the social structural factors which theorists and practitioners have identified (Conger and Kanungo, 1988; Kanter, 1983; Thomas and Velthouse, 1990) are predicted to have a positive direct effect on subordinates’ trust and subsequently the extent of employees’ perceived psychological empowerment. These are: (1) the organic or mechanistic nature of the organization, (2) the extent of social political support, (3) the extent of re- source and information support, and (4) the human- and innovation-oriented organization culture. Organization culture was measured with the eight-item human- and innovation-oriented values extracted from the Competing Values Model of Organizational Culture (Quinn and Spreitzer, 1993) | Conger, J. A. and R. N. Kanungo. 1988. “The Empowerment Process: Integrating Theory and Practice.” Academy of Management Review 13 (3): 471–482.; Spreitzer, G. M. 1996. “Social Structural Characteristics of Psychological Empowerment. Academy of Management Journal. 49 (2): 483–504; Kanter, R. M. 1986. “Empowering People to Act on Ideas.” Executive Excellence (February): 5–6.; Quinn, R. E. 1988. Beyond Rational Management: Mastering the Paradoxes and Competing Demands of High Performance. San Francisco, CA: Jossey