# APPENDIX C DATA ABSTRACTION FORM

1. Sample size, units (rr)
2. Location
3. Is there an intervention that demonstrates a change in culture of innovation as an outcome?
  ○ No intervention
  ○ Yes (name intervention/program)
  ○ Unclear
4. Metric Characteristics (must include at least 1 measure of culture of innovation, otherwise say none)
  ○ None
  ○ Yes (name, or characteristics/traits identified/measured, number of items/scales, include citation)
  ○ Unclear
5. Data Analysis
  ○ Descriptives
  ○ Validation
  ○ Mediation (SEM)/path analysis
  ○ Regression analysis
  ○ Other
6. Study design
  ○ Cross-sectional
  ○ RCT
  ○ Pre-post
  ○ Time-series/repeated surveys
  ○ Interview/Focus group
  ○ Other
7. Findings from abstract