# APPENDIX B PEER REVIEWER COMMENTS AND RESPONSES

Comment | Response
The objectives of the research, and how the research might be translated into practice, could use additional detail in the report. | We have revised the report to incorporate additional details regarding objectives and translation into practice.
I feel there is a need for a little more precision, in the language throughout the report, to remind the reader when the review is focused exclusively on innovation culture as defined and cultivated within a healthcare setting, and when it looks/draws conclusions relevant beyond that setting. Innovation is a topic of enormous interest in economics, management, etc., and reviewing all of that literature would be well beyond the scope of this review, and would not necessarily yield more useful result for a health care audience. However it would be good to be more consistent in being clear about this throughout the review. Some of the more striking examples:; - Key Question 1 could refer to “the literature within medical and/or health services research” not just “the literature;; - “Key Questions 2 and 3 similarly need their scope more explicitly defined;; - in Appendix A, I read these search strategies as including both strategies requiring “health” or “medical” or “hospital” and strategies that did not (but within Medline). It surprises me that only 480 potential articles were identified if the search criteria did not always include a need for a healthcare setting (maybe that has to do with what Medline indexes). A line or 2 clarifying what academic fields/disciplines were most likely to not be captured would be helpful; | We have added appropriate wording to make clear that our focus is a healthcare setting throughout the report and revised all 3 key questions to be more specific in this regard. We would agree that innovation is a topic of enormous interest in economics, management, etc., and reviewing all of that literature would be well beyond the scope of this review, which was focused specifically on culture rather than innovation more broadly. We have added the number of citations to each of the searches in Appendix A. We chose databases intending to capture all relevant academic fields/disciplines, so we are unable to comment on what we may have potentially missed with our strategy, as we would have incorporated these missed areas if they were known to us.
- Emphasizing somehow which measures were developed (or validated) in a healthcare setting, and which originated in other fields, would be of interest. | For a few of the measures identified in more than 1 included study, we have added information about whether measures were developed or validated in a healthcare setting. However, it is beyond the scope of this review to identify and describe all research contributing to the development and validation of the specific measures we identified in the course of our review. While in some instances the literature we identified had described the measure, its development and/or validation process, this was often not the case, and would require additional search and literature synthesis.
The search terms described in Appendix A (Page 27), focusing on “culture of innovation” and related terms, may have missed a portion of the large body of research on “organizational innovation,” which is similarly relevant to the topic at hand but may not use identical terminology. It looks like the exact search terms may have caught many of those articles, but it is difficult to know for certain. | The literature captured with the term “organizational innovation” was very broad, and often described innovation outside of an organization’s culture, which was the focus of this report. As such, this was too broad a term for our search strategy.
Executive Summary; Introduction—I think you need to add a sentence or phrase indicating why a culture of innovation is valuable.; Data abstraction and quality assessment—The second paragraph, and particularly the first sentence, is unclear. What do you mean by the culture of innovation doesn’t have instruments to assess the quality of studies?; Results; KQ1 This results summary doesn’t really answer the question, how is culture of innovation defined. Could you instead summarize the findings themselves?; KQ2 Similarly, rather than counts about where the metrics come from, can you describe the metrics?; KQ3 This summary also does not describe the key characteristics and outcomes of the programs. Can you instead describe what the programs did and what outcomes they achieved? If the studies were not sufficiently rigorous to warrant reporting their findings, you could say that instead.; Discussion—Just noting that this section is quite a bit longer and more detailed than the other sections of the executive summary, so feels somewhat inconsistent. Perhaps you could find a middle ground. I do think some of the previous sections could use more detail. | We have revised the executive summary to incorporate suggested changes.(pg 6–8); In regards to comment about KQ3, while there were some signals of positive culture of innovation outcomes as indicated by the programs identified in the review, the low level of certainty of evidence due to the very low response rates and/or small sample sizes from the studies limited our ability to draw conclusions.
p.10 line 14. I think it would help to acknowledge that there are multiple facets of organizational culture (eg, safety culture, innovation culture) and that scholarship has increasingly acknowledged the value of focusing on specific types. This seems like a missing link between organizational culture overall and innovation culture in particular.; p.10 line 17. This paragraph needs to do a better job of setting up the questions, particularly KQ1. In other words, if INPOWR defined a culture of innovation as having 4 dimensions, and that is satisfactory, then why are you asking how culture of innovation is defined? Presumably, you were interested in how others defined culture of innovation and how other definitions related to the INPOWR model. | We have revised the introduction to acknowledge that there are multiple facets of organizational culture and that scholarship has increasingly acknowledged the value of focusing on specific types. We have also revised this section to do a better job of setting up the 3 key questions. (p.9)
p.11 line 26. Search strategy. In your search of culture of innovation and culture of creativity, did related terms arise? If so, it would be worth describing how you dealt with this situation. For example, once noted, did you pursue the related terms? About how often did it happen? You can leave what terms emerged for the results.; p.12 line 10. Quality assessment. I’m still struggling with this. I can understand saying that a quality assessment was beyond the intended scope of this review, but I’m a little doubtful that it wouldn’t be possible to assess the quality of studies you identified. Even if specific instruments for assessing quality of studies about culture of innovation are not available, if the team wanted to assess study quality, could you not have borrowed more generic evaluation criteria? | This area is extremely nebulous and as such, we decided to stick to a narrower scope for our searches in accordance to the intended use of this report. For example, there is definite overlap between culture of innovation and organizational learning and patient safety culture. However, organizational learning and patient safety culture would each require an entire review. We have described this challenge in research gaps and future research section. (p.28); We struggled with finding an appropriate quality assessment tool for our included studies. After consulting with some methodological experts, they agreed with our approach given the challenges of this report’s scope. Typically, quality assessments are used to describe the risk of bias for outcomes from the evaluation of an intervention. As the majority of our studies did not include interventions, this would not help describe the body of literature we identified overall, nor would it help readers interpret key questions 1 or two. We were not able to identify an existing assessment or determine a set of criteria that would be suitable to assess quality for studies defining culture of innovation or using a metric, as is the focus of these 2 questions. While there are quality assessment criteria for the development of a metric, not all our included studies described this process, and applying these criteria to studies with a different set of aims would not be appropriate.; For the subset of intervention studies, we do describe the major risks of bias and their considerable impact on the interpretation of the studies, but we do so qualitatively rather than assigning quality assessment scores, since there are only 4 studies to describe and their issues with small sample size and/or low response rates make any other risk of bias of secondary concern.
Figure 1: Suggest you revise “Program” to read “Program and metrics” | We have added “program and” to Figure 1. (p.12)
p.16 line 12. If Anderson and West turned out to be the framework linking most of the studies, why do you introduce this ESP report by focusing on INPOWR? Alternatively, since you began by introducing the INPOWR framework, could you at least comment on its relevance in the literature you reviewed? | We have revised the introduction to better link to the contents of our results.
p.17 KQ2. This section left me wondering what was in these metrics and how they compared? Can you say something about which or under what conditions different metrics seemed more valuable? | Because of many single-use or adaptations, it is hard to distinguish a pattern among metrics identified from included studies. In addition, while some instruments were available in the included study, most were not. In order to further explore the content of these metrics we would have had to conduct a comprehensive qualitative content analysis which proved to be out of scope for this project. We are considering this as a future extension of our current work if time permits.
p.19 line 25. Can you explain what the UK intervention meant by leadership learning? If that is the intent of the Figure on Leadership Learning Programs, you should make that clear.; P.20 line 40. What is a clinical supervision intervention? Again, refer to the figure if needed. | We have added figure headings and referred to them in-text. (p.22–23)
p.21 line 24. I think it would be helpful to list the Anderson and West dimensions.; p.21 line 35. It would also be helpful to describe the Team Climate Inventory in more detail.; p.21 line 45. You could summarize by saying that interventions so far have emphasized x, y, z. | We have listed the Anderson and West dimensions, described the Team Climate Inventory in more detail, and added more information about interventions. (p.25–26)
Publication Bias section has some grammatical and spelling errors and needs additional copy editing (Page 22). | We have revised the publication bias section. We have also added a relevance to VA subsection. (p.27)
Additional information on potentially generalizable findings from the 4 key studies reviewed would strengthen the Discussion section, as would information on how interventions and measures listed might be adapted and implemented in the specific context of the VHA system. This might be structured as a new subsection. | We have revised KQ3 and added details about the interventions. However, the low level of certainty of evidence due to very low response rate and/or small sample size reported in the intervention studies limited our ability to provide generalizable findings.
Figure 3 - the wordcloud - is not particularly helpful, especially since the /most common words are “innovation” and “innovative”. It might be interesting to see how such a word cloud compares to 1 generated by searching management literature outside of health care, but that is beyond the scope of this review. | While authors agree comparing to a broader literature would of great interest, we also agree this is beyond the scope of this review.
Although excluded from the evidence reviewed, the 5 articles excluded for being commentary only might be useful to review and comment on in the Discussion, as part of describing future areas of research. | We agree that reviewing commentaries might be useful for identifying future areas of research. However, there were a total of 78 publications excluded for being editorials/commentary. Reviewing these 78 publications to identify future areas of research would be out of scope for this review.
Reading this report, I was struck by how much overlap there is between research on fostering leadership and research on fostering innovation (the UK study, where a leadership training program used innovation climate as an outcome, is a strong example of this). Do some concepts of innovation rely more on innovation from “above” by people in formal leadership positions, and do other concepts/approaches to innovation rely more on distributed leadership/initiative from “below?” This is beyond the scope of the key questions but strikes me as an interesting question for future research. | We agree that this is an interesting question for future research and have noted this in the discussion section.
It is unfortunate but not surprising there is not a larger evidence base of studies describing interventions within healthcare to foster innovation. The report has summarized well what exists, and gathering in 1 report all the different definitions and tools used to try to capture innovation climate may prove useful for others wanting to know where the state of the evidence and practice stands. | Thank you for the comment.
p4, 5–7: titles should be capitalized, ie, Director of Operations…; Director of Programming;; p4, 22: omission -“…Myers and the…”; p4, 42: omission- Discovery, Education and Affiliate Networks | We have made the suggested changes. (p.iii)