# APPENDIX A SEARCH STRATEGIES

## DATABASE SEARCHED & TIME PERIOD COVERED: Web of Science – inception – 9/18/2020

237 results

### Search Strategy

TS=(((“culture of innovation” OR “culture of creativity” OR (((innovat* or creativ*) NEAR/2 (culture* OR climate*))

AND

(management OR organization OR staff OR personnel OR employ*))) AND (health* OR hospital* OR medical)))

## DATABASE SEARCHED & TIME PERIOD COVERED: OVID MEDLINE – Inception – 9/18/2020

183 results

### Search Strategy

(“culture of innovation” OR “culture of creativity” OR (((innovat* or creativ*) adj2 (culture* OR climate*))

AND

(management OR organization OR staff OR personnel OR employ*))).ti,ab

## DATABASE SEARCHED & TIME PERIOD COVERED: PsycINFO – inception to 9/18/2020

155 results

### Search Strategy

(“culture of innovation” OR “culture of creativity” OR (((innovat* or creativ*) NEAR/2 (culture* OR climate*))

AND

(management OR organization OR staff OR personnel OR employ*))) AND (health* OR hospital* OR medical)